# Supplementary Materials

- Excluded studies (XLSX)
- Risk of Bias (XLSX)
- Baseline Characteristics (XLSX)
- Design Details (XLSX)
- Procedure Details (XLSX)
- Systematic Review Details- ET (XLSX)
- Systematic Review Details - PD (XLSX)
- Systematic Review Details-Other (XLSX)
- Outcomes- Essential Tremor (XLSX)
- Outcomes- Parkinsons Disease (XLSX)
- Outcomes- Dystonia Conditions (XLSX)
- Peer Review Feedback (XLSX)

## VA Related Documents

Supplementary Materials (XLSX)