# REFERENCES

1 Uscher-Pines L, Pines J Fau - Kellermann A, Kellermann A Fau - Gillen E, . Emergency department visits for nonurgent conditions: systematic literature review. (1936–2692 (Electronic)).
2 Weinick RM, Burns Rm Fau - Mehrotra A, Mehrotra A. Many emergency department visits could be managed at urgent care centers and retail clinics. (1544–5208 (Electronic)).
3 Poon SJ, Schuur JD, Mehrotra A. Trends in Visits to Acute Care Venues for Treatment of Low-Acuity Conditions in the United States From 2008 to 2015. JAMA Intern Med. 2018;178(10):1342–1349.30193357
4 Centers for Disease Control and Prevention. National Center for Health Statistics. Ambulatory Health Care Data. 2017. Available at: https://www.cdc.gov/nchs/ahcd/web_tables.htm#2017. Accessed December 14, 2020.
5 Centers for Disease Control and Prevention. Using Telehealth to Expand Access to Essential Health Services during the COVID-19 Pandemic. 2020. Available at: https://www.cdc.gov/coronavirus/2019-ncov/hcp/telehealth.html. Accessed December 14, 2020.
6 Bashshur RL, Howell JD, Krupinski EA, . The Empirical Foundations of Telemedicine Interventions in Primary Care. Telemed J E Health. 2016;22(5):342–75.27128779
7 Wosik J, Fudim M, Cameron B, . Telehealth transformation: COVID-19 and the rise of virtual care. J Am Med Inform Assoc. 2020;27(6):957–962.32311034
8 Daniel H, Sulmasy LS, Health, . Policy recommendations to guide the use of telemedicine in primary care settings: an American College of Physicians position paper. Ann Intern Med. 2015;163(10):787–9.26344925
9 Verma S. Early Impact of CMS Expansion of Medicare Telehealth During COVID-19. Health Affairs blog [online]. https://www.healthaffairs.org/do/10.1377/hblog20200715.454789/full/. Accessed December 14, 2020.
10 Koonin LM, Hoots B, Tsang CA, . Trends in the Use of Telehealth During the Emergence of the COVID-19 Pandemic - United States, January-March 2020. MMWR Morb Mortal Wkly Rep. 2020;69(43):1595–1599.33119561
11 Pikoulis E, Solomos Z, Riza E, . Gathering evidence on the decreased emergency room visits during the coronavirus disease 19 pandemic. Public Health. 2020;185:42–43.32535391
12 Bestsenny O, Gilbert G, Harris A, . Telehealth: A quarter-trillion-dollar postCOVID-19 reality? 2020. Available at: https://www.mckinsey.com/industries/health-care-systems-and-services/our-insights/telehealth-a-quarter-trillion-dollar-post-covid-19-reality# (https://www.mckinsey.com/industries/health-care-systems-and-services/our-insights/telehealth-a-quarter-trillion-dollar-post-covid-19-reality). Accessed December 14, 2020.
13 Affairs DoV. Telehealth/Connected Care.
14 Clinical Contact Center ready to answer Veterans’ questions. 2020.
15 Moher D, Liberati A, Tetzlaff J, . Preferred reporting items for systematic reviews and meta-analyses: the PRISMA statement. J Clin Epidemiol. 2009;62(10):1006–12.19631508
16 Cochrane Effective Practice and Organisation of Care (EPOC). Suggested risk of bias criteria for EPOC reviews. EPOC Resources for review authors, 2017. Available at: http://epoc.cochrane.org/resources/epoc-resources-review-authors Accessed May 12, 2020.
17 Sterne JAC, Savović J, Page MJ, . RoB 2: a revised tool for assessing risk of bias in randomised trials. BMJ. 2019;366:l4898.31462531
18 National Institutes of Health. NHLBI. Study quality assessment tools. Available at: https://www.nhlbi.nih.gov/health-topics/study-quality-assessment-tools. Accessed January 7, 2022.
19 Sterne JA, Hernán MA, Reeves BC, . ROBINS-I: a tool for assessing risk of bias in non-randomised studies of interventions. BMJ. 2016;355:i4919.27733354
20 Hultcrantz M, Rind D, Akl EA, . The GRADE Working Group clarifies the construct of certainty of evidence. J Clin Epidemiol. 2017;87:4–13.28529184
21 Ashwood JS, Mehrotra A, Cowling D, . Direct-to-consumer telehealth may increase access to care but does not decrease spending. Health Aff (Millwood). 2017;36(3):485–491.28264950
22 Cragg DK, McKinley RK, Roland MO, . Comparison of out of hours care provided by patients’ own general practitioners and commercial deputising services: a randomised controlled trial. I: The process of care. BMJ. 1997;314(7075):187–9.9022434
23 Gordon AS, Adamson WC, DeVries AR. Virtual Visits for Acute, Nonurgent Care: A Claims Analysis of Episode-Level Utilization. J Med Internet Res. 2017;19(2):e35.28213342
24 Knowles E, O’Cathain A, Turner J, . Effect of a national urgent care telephone triage service on population perceptions of urgent care provision: controlled before and after study. BMJ Open. 2016;6(10):e011846.
25 Lovell T, Albritton J, Dalto J, . Virtual vs traditional care settings for low-acuity urgent conditions: An economic analysis of cost and utilization using claims data. J Telemed Telecare. 2019:1357633X19861232.
26 McKinley RK, Stevenson K, Adams S, . Meeting patient expectations of care: The major determinant of satisfaction with out-of-hours primary medical care? Fam Pract. 2002;19(4):333–338.12110550
27 Salisbury C. Postal survey of patients’ satisfaction with a general practice out of hours cooperative. BMJ. 1997;314(7094):1594–8.9186172
28 Sen B, Clay H, Wright J, . Impact of Emergency Medicine Consultants and Clinical Advisors on a NHS 111 Clinical Assessment Service. Emerg Med J. 2019;36(4):208–212.30940680
29 Shipman C, Payne F, Hooper R, . Patient satisfaction with out-of-hours services; how do GP co-operatives compare with deputizing and practice-based arrangements? J Public Health Med. 2000;22(2):149–54.10912552
30 Tranberg M, Vedsted P, Bech BH, . Factors associated with low patient satisfaction in out-of-hours primary care in Denmark - a population-based cross-sectional study. BMC Fam Pract. 2018;19(1):15.29325520
31 Turner J, O’Cathain A, Knowles E, . Impact of the urgent care telephone service NHS 111 pilot sites: a controlled before and after study. BMJ Open. 2013;3(11):e003451.
32 Wilson P, McConnachie A, O’Donnell CA, . Assessing dissatisfaction with an out of hours service: reasons and remedies. Health Bulletin. 2001;59(1):37–44.12811909
33 McKinley RK, Cragg DK, Hastings AM, . Comparison of out of hours care provided by patients’ own general practitioners and commercial deputising services: a randomised controlled trial. II: The outcome of care. BMJ. 1997;314(7075):190–3.9022435
34 McKinley RK, Manku-Scott T, Hastings AM, . Reliability and validity of a new measure of patient satisfaction with out of hours primary medical care in the United Kingdom: development of a patient questionnaire. BMJ. 1997;314(7075):193–8.9022436
35 Department of Health and Human Services. Office of Disease Prevention and Health Promotion. Healthy People 2020: Access to health services. Available at: https://www.healthypeople.gov/2020/topics-objectives/topic/Access-to-Health-Services. Accessed January 6, 2022.
36 Lattimer V, George S, Thompson F, . Safety and effectiveness of nurse telephone consultation in out of hours primary care: randomised controlled trial. The South Wiltshire Out of Hours Project (SWOOP) Group. BMJ. 1998;317(7165):1054–9.9774295
37 Shi Z, Mehrotra A, Gidengil CA, . Quality Of Care For Acute Respiratory Infections During Direct-To-Consumer Telemedicine Visits For Adults. Health Aff (Millwood). 2018;37(12):2014–2023.30633682
38 Wallace E, Cronin S, Murphy N, . Characterising patient complaints in out-of-hours general practice: a retrospective cohort study in Ireland. Br J Gen Pract. 2018;68(677):e860–e868.30455221
39 Lake R, Georgiou A, Li J, . The quality, safety and governance of telephone triage and advice services - an overview of evidence from systematic reviews. BMC Health Serv Res. 2017;17(1):614.28854916
40 Boggan JC, Shoup JP, Whited JD, . Effectiveness of Acute Care Remote Triage Systems: a Systematic Review. Journal of General Internal Medicine. 2020;02:02.
41 Sexton V, Dale J, Bryce C, . Service use, clinical outcomes and user experience associated with urgent care services that use telephone-based digital triage: a systematic review. BMJ Open. 2022;12(1):e051569.
42 Bunn F, Byrne G, Kendall S. The effects of telephone consultation and triage on healthcare use and patient satisfaction: a systematic review. Br J Gen Pract. 2005;55(521):956–961.16378566
43 Richards DA, Meakins J, Godfrey L, . Survey of the impact of nurse telephone triage on general practitioner activity. Br J Gen Pract. 2004;54(500):207–210.15006127
44 Adam GP, Springs S, Trikalinos T, . Does information from ClinicalTrials.gov increase transparency and reduce bias? Results from a five-report case series. Syst Rev. 2018;7(1):59.29661214
45 Robinson KA, Saldanha IJ, McKoy NA. Development of a framework to identify research gaps from systematic reviews. J Clin Epidemiol. 2011;64(12):1325–30.21937195
46 Jeganathan S, Prasannan L, Blitz MJ, . Adherence and acceptability of telehealth appointments for high-risk obstetrical patients during the coronavirus disease 2019 pandemic. Am J Obstet Gynecol MFM. 2020;2(4):100233.32984803
47 Vidal-Alaball J, Acosta-Roja R, Pastor Hernandez N, . Telemedicine in the face of the COVID-19 pandemic. Aten Primaria. 2020;52(6):418–422.32402477
48 Bodenheimer T, Sinsky C. From triple to quadruple aim: care of the patient requires care of the provider. Ann Fam Med. 2014;12(6):573–6.25384822