# ACKNOWLEDGMENTS

The authors are grateful to Stacy Lavin, PhD, and Liz Wing, MA, for editorial and citation management support, and the following individuals for their contributions to this project:

## Operational Partners

Operational partners are system-level stakeholders who help ensure relevance of the review topic to the VA, contribute to the development of and approve final project scope and timeframe for completion, provide feedback on the draft report, and provide consultation on strategies for dissemination of the report to the field and relevant groups.

- Leonie Heyworth, MD MPH
  Director of Synchronous Telemedicine, Office of Connected Care
  San Diego VA Medical Center
- Chad Kessler, MD
  National Program Director, Emergency Medicine
  Durham VA Health Care System
- Joshua Geiger, MSPsy
  Health System Specialist, Specialty Care Service
  Executive Officer for Emergency Medicine
  VACO 10P11

## Technical Expert Panel

To ensure robust, scientifically relevant work, the TEP guides topic refinement; provides input on key questions and eligibility criteria, advising on substantive issues or possibly overlooked areas of research; assures VA relevance; and provides feedback on work in progress. TEP members are listed below:

- Irwin Barr, MD,
  Medical Advisor
  Montana VA Health Care System
- Maria C Bouchard, NP,
  Nurse Practitioner
  VA Greater Los Angeles Healthcare System
- Laurie K. Conti, MPT,
  Health System Specialist
  Clinical Resource Hub Business Operations Director
  VISN 4
- Stephanie Deaner, PhD,
  Telehealth Program Manager
  VISN 12

## Peer Reviewers

The Coordinating Center sought input from external peer reviewers to review the draft report and provide feedback on the objectives, scope, methods used, perception of bias, and omitted evidence. Peer reviewers must disclose any relevant financial or non-financial conflicts of interest. Because of their unique clinical or content expertise, individuals with potential conflicts may be retained. The Coordinating Center works to balance, manage, or mitigate any potential nonfinancial conflicts of interest identified.