# DISCUSSION

The COVID-19 pandemic has underscored the need for timely and accessible health care that fits the level of illness severity. Challenges abound as patients and health care providers alike continue to seek alternative ways to access and deliver appropriate and high-quality urgent care in the context of the current public health crisis. The promise of tele-urgent care is to decrease barriers and improve access to needed low-acuity health care.^39^ Also, expanding access to urgent care via virtual modalities may allow more appropriate utilization of scarce and costly in-person emergency department services for high-acuity health conditions.^3,4^ Yet there are many unanswered questions about the effects of tele-urgent care on key clinical and health system outcomes. Thus, we sought to evaluate the effectiveness of tele-urgent care (KQ 1A) and adverse effects of tele-urgent care (KQ 2A) and explore differences in these key metrics by provider characteristics and tele-urgent care modality (KQ 1B, KQ 2B). To assess the effectiveness of tele-urgent care, we examined its impact on outcomes meaningful to VHA operations partners and vetted with our panel of technical experts.

Our systematic review is innovative in that it included a definition of “tele-urgent care” that sought to distinguish tele-urgent care systems from other virtual care services that are focused solely on evaluation and triage and do not include treatment by a prescribing provider (eg, virtual after-hours advice services, remote triage systems). We also sought to examine both objective and patient-reported outcomes and include a wide variety of experimental and observational designs, including cross-sectional studies. As such, we identified 4 experimental studies (1 RCT, 1 cluster RCT, 2 controlled before-and-after) and 12 observational studies (4 cohorts, 8 cross-sectional). No studies specifically addressed Veterans or were conducted in VHA.

## KEY QUESTION 1 SUMMARY

We identified 13 studies that evaluated tele-urgent care across 5 outcomes of interest (ie, health care utilization, patient satisfaction, cost, health care access, and case resolution). Six studies reported health care utilization, 7 reported patient satisfaction, 4 reported cost, 2 reported health care access, 2 reported case resolution, and none reported patient safety. They consisted of 1 RCT, 2 controlled before-and-after studies, 7 cross-sectional studies, and 3 cohort studies. Overall, we found limited evidence on the impact of tele-urgent care on health care access (2 studies), case resolution (2 studies), and patient safety (no studies). None of the studies that met KQ 1 eligibility criteria provided analysis by provider characteristics (ie, specialty, amount of telehealth experience, training), and studies did not provide sufficient information to conduct study-level subgroup analysis. There were insufficient studies to explore the role of tele-urgent care by mode (ie, telephone, video) for any outcome. As a result, we were unable to address KQ 1B.

Next, we briefly summarize findings on the 3 outcomes prioritized by VHA operations partners as the most important for decision-making. Table 8 summarizes the COE ratings for these 3 outcomes.

### Health Care Utilization

Six studies assessed the impact of tele-urgent care on health care utilization. Most had at least moderate ROB. Two studies suggested that the introduction of tele-urgent care may increase overall (ie, “new utilization”) health care utilization (very low COE). Four studies assessed subsequent health care utilization (ie, outpatient visits, ED, inpatient stays) after initial index tele-urgent care with no evidence that subsequent outpatient utilization significantly differs by organizational level of the virtual care (ie, local vs regional systems) or by profession of the initial staff conducting the triage portion of the tele-urgent care interaction (eg, nonclinical call handler, nurse vs general practitioner). When comparing the initial site of urgent care on subsequent health care utilization, care sought virtually consistently demonstrated lower subsequent health care utilization than care initially sought in the ED. Yet no clear pattern emerged when comparing urgent care initially sought via virtual mode or other, in-person venues (eg, urgent care centers, retail health clinics) outside the ED. It is important to note that most studies did not control for condition severity, which likely affects inferences about the impact of tele-urgent care on subsequent health care utilization. The COE for the impact of tele-urgent care on subsequent health care utilization was, at most, rated low.

### Patient Satisfaction

Seven studies of varied quality reported on patient satisfaction with tele-urgent care. Differences in patient satisfaction were not consistently observed by triage decision of tele-urgent care interaction (telephone care management for self-care vs clinic visit vs home visit) or by relationship of the care provider to the clinic organization (external “deputizing” physicians vs practice-based and/or cooperative physicians). Generally, patients expressed the greatest satisfaction when the care they received matched their expectations for care. Overall COE for this outcome was rated as low or very low.

### Health Care Cost

Four US-based studies assessed the cost of delivering tele-urgent care. All but 1 cross-sectional study were rated as moderate to serious ROB considerations. Across included studies, index costs (low COE) and total costs (very low COE) for care associated with tele-urgent visits for low-acuity conditions were lower for tele-urgent visits compared with in-person urgent care (eg, ED, in-person urgent care centers). Yet 1 study supported that tele-urgent care may increase overall health care spending via increased access to on-demand care for low-acuity conditions.

### Certainty of Evidence for Key Outcomes

We conducted COE ratings for the outcomes identified by our stakeholders as critical to decision-making. These assessments reflect the degree of confidence we have in our summary findings. For each outcome of interest, we present the COE by the utilization type (eg, overall, outpatient, emergency department), the overall satisfaction with care received by tele-urgent care systems, and the index visit cost and total costs (Table 8).

We identified very low COE that tele-urgent care reduces subsequent ED utilizations. The evidence reporting no effect of tele-urgent care on subsequent outpatient care utilization was low certainty for randomized studies and very low certainty for observational studies. We found very low COE that tele-urgent care systems reduced subsequent hospitalization. The evidence reporting mixed effects of tele-urgent care systems on overall trends in health care utilization was determined to be very low certainty. We have low certainty for randomized studies and very low certainty for observational studies that tele-urgent care has no effect or reduces patient satisfaction. We identified low COE that tele-urgent care reduces index visit costs compared to in-person care. The evidence reporting mixed effects of tele-urgent care on total costs was evaluated to be very low certainty.

Table 8 Certainty of Evidence for Primary Outcomes of Effects of Tele-urgent Care

Outcome | Number of Studies (Patients or Encounters) | Range of Effects | Certainty of Evidence (Rationale)
Utilization
ED utilization | 3 observational (5349,689) | One study reported 0.1%; to 5.2% fewer ED visits, 1 study reported RRs between; 1.29 (95% CI 0.75 to 1.82) and 5.53 (95% CI 3.34 to 7.71) times less risk for ED visits, and 1 study reported 0.1% decrease in ED use | Very low certainty (rated down for serious risk of bias)
Outpatient care | 1 randomized (2,152) | 2.5% decrease in outpatient visits | Low certainty (rated down for serious risk of bias and serious imprecision)
Outpatient care | 3 observational (349,689) | One study reported range from 2.5% increase to 6.1% decrease in outpatient visits, 1 study reported a 2.5% (95% CI −3.5% to 8.5%) increase in outpatient visits, and 1 study reported RRs between 0.85 (95% CI 0.77 to 0.93) and 1.50 (95% CI 1.35 to 1.64) times less risk for primary care visits | Very low certainty (rated down for very serious inconsistency and serious imprecision)
Hospitalization | 2 observational (72,526) | One study reported a range of 0.1% to 0.8% decrease in hospitalization, and 1 study reported RRs between 1.57 and 6.74 times less risk for hospitalization | Very low certainty (rated down for serious inconsistency and very serious imprecision)
Overall health care utilization | 2 observational (20,602,943) | One study reported a range of 3.9% to 9.6% decrease in other forms of health care utilization, and 1 study reported that 88.2% of the telehealth visits were additional visits attributable to introduction of tele-urgent care | Very low certainty (rated down for serious risk of bias and very serious inconsistency and serious imprecision)
Patient Satisfaction
Total satisfaction | 1 randomized (2,152) | 61.8% (95% CI 59.9 to 63.7) satisfaction with deputizing service vs 70.7% (95% CI 68.1 to 73.2) satisfaction with practice doctors | Low certainty (rated down for serious risk of bias, serious indirectness)
Total satisfaction | 6 observational (41,505) | One study reported no significant difference between GP cooperatives, practice-based, and deputizing services for out of hours care; 1 study reported a mean difference of −0.12 (p=0.041) between deputizing services and cooperatives; 1 study reported an OR of 0.97 (95% CI 0.69 to 1.37) for excellent patient satisfaction before compared to after NHS 111; 1 study reported higher dissatisfaction (OR 6.43, 95% CI 3.35 to 12.32) when patients expected to receive in-person care but received tele-phone advice; another study reported that there was greater satisfaction associated with cooperative vs deputizing service (p = 0.02); and the last study reported that patients were more dissatisfied with telephone care vs clinic or home visit (p <0.001) | Very low certainty (rated down for serious indirectness)
Cost
Index | 2 observational (72,526) | One study reported a range relative decrease in cost between 28.87 (95% CI 28.39 to 29.36) and 1.52 (95% CI 1.49 to 1.54), and another study reported a relative decrease in cost ranging from 2.54 (95% CI 2.46 to 2.62) to 30.74 (95% CI 29.67 to 31.81) | Low certainty (rated down for observational study designs)
Total | 4 observational (20,675,469) | One study reported a range of $3 decrease to $723 increase in cost compared to $1 decrease in tele-urgent care during the same period. One study reported a range of 1.11 to 6.12 relative decrease in cost. Another study reported an annual spending increase of $45 (95% CI 1.49 to 1.54) per person comparing between tele-urgent users and non-users. The last study reported a relative decrease in cost between 1.54 (95% CI 1.18 to 1.91) and 7.93 (95% CI 5.78 to 10.09) | Very low certainty (rated down for serious risk of bias and for serious inconsistency)

## KEY QUESTION 2 SUMMARY

We found little evidence on the adverse effects prioritized by VHA operations partners (ie, inappropriate treatment, misdiagnosis, delayed diagnosis, provider burnout). We identified only 3 studies in total that met our prespecified eligibility criteria; none addressed provider burnout. All included studies had ROB concerns. One moderate ROB retrospective cohort study explored inappropriate treatment outcomes and found similar or better guideline-concordant antibiotic use for acute upper respiratory infections when treatment was delivered via direct-to-consumer telemedicine compared to in-person primary care or ED visits. For misdiagnosis and delayed diagnosis, one fair ROB cross-sectional study reported a small proportion of clinical safety complaints resulting from telephone-based after-hours care, many of which were not validated on objective review. None of the studies that met KQ 2 eligibility criteria provided analysis by provider characteristics (ie, specialty, amount of telehealth experience, training), and studies did not provide sufficient information to conduct study-level subgroup analysis. There were insufficient studies to explore the role of tele-urgent care by mode (ie, telephone, video) for any outcome. As a result, we were unable to address KQ 2B.

## PRIOR SYSTEMATIC REVIEWS

Most prior systematic reviews on virtual care that were conceptually similar to this topic differed in their focus on initial assessment of acute, undifferentiated, or unscheduled care (ie, remote triage), telephone modality only, or non-urgent conditions.^40,41^ Six prior reviews focused on similar outcomes but were not able to conduct quantitative synthesis due to high heterogeneity of interventions, outcomes, and designs. One systematic review evaluated patient satisfaction with remote triage but only included telephone-delivered advice.^42^ Another sought to include diverse remote triage modalities but only identified those delivered by telephone.^40^ These prior reviews reported mixed findings, with 1 review reporting the majority of included studies did not demonstrate a decrease in primary care, while another found that most studies demonstrated a decrease in primary care utilization.^42^ When comparing the initial site of urgent care on subsequent health care utilization, care sought virtually consistently demonstrated lower subsequent health care utilization than care initially sought in the emergency department. Yet no clear pattern emerged when comparing tele-urgent care to urgent care sought at in-person venues (ie, urgent care centers, retail health clinics, primary care clinics).

For overall patient satisfaction with care, 1 prior review found high levels of satisfaction with virtual care.^43^ Two other reviews reported mixed results that are more consistent with our interpretation of the data that patients expressed the greatest satisfaction when the care they received matched their expectations for care (eg, receiving in-person care when they expected to receive in-person care).^40,41^ For costs, 1 prior review reported that remote triage did not significantly differ in total costs from in-person primary care or by organizational level of the remote triage system (ie, local vs national triage system).^40^ In contrast, our review found that index costs and total costs for care associated with tele-urgent visits for low-acuity conditions were lower for tele-urgent-type visits compared with similar types of visits for in-person settings (eg, ED, in-person urgent care centers). Consistent with our finding, other reviews found little data on safety outcomes and adverse events. Of note, 1 review concluded that the safety and quality of remote triage appeared to be linked to the context of the broader system in which the virtual care system was rooted, including policy priorities, health care costs, demographic and cultural factors, and technical infrastructure.^39^ Likely, this applies to tele-urgent care systems as well; we were unable to address this finding in our review.

## CLINICAL AND POLICY IMPLICATIONS

Demand for telehealth has been increasing—even before the COVID-19 pandemic. Tele-urgent care, as a subset of services deliverable by virtual approaches at a distance, may be an appropriate means for delivering high-quality care for low-acuity conditions. Given that findings from this review were often from European systems of care, the applicability to the VA system versus other US systems of care is fairly strong. Centralized payment and delivery models found in European countries are most similar to our VA system of care and have lessons for us to learn. There was, however, little cohesion across studies of tasks within care models or standardization in how costs are measured.

Patient satisfaction with tele-urgent care appeared somewhat lower when telephone consultation was a part of tele-urgent care delivery. This suggests that in-person clinic- and home-based care modes may offer the face-to-face experience patients are seeking when reaching out for their urgent care needs. Notably, no included studies were conducted via video visits. Historically, patient satisfaction with video visits has been higher that telephone visits. Video calls may be the answer to optimizing patent satisfaction for virtual visits, but the United States is still hampered by internet broadband challenges in both urban and rural locales, not to mention the personal financial resources needed to purchase devices workable with a video platform. Additionally, video may feel intrusive compared to telephone communication alone. The VA system, if it pivots to long-term tele-urgent care offerings, will need to continue shoring up patients’ access by underwriting devices or adding more robust assessments of local broadband to mitigate those challenges.

While the costs of tele-urgent care were not measured uniformly across the included studies, they generally included direct care services plus laboratory, imaging, and pharmacy costs. According to the included studies, virtual visits cost less than other in-person modes of care. However, the introduction of tele-urgent care likely introduces new costs related to staff training, patient preparation for a virtual encounter, technical support, and clinical workflow acclimation.

Delivering care at a distance requires accurate history-taking, adequate assessment with limited means, optimized communication and rapport building, and impeccable professional credentialing. Proactively managing patient expectations of tele-urgent care while compelling staff to follow evidence-based guidelines can improve rates of inappropriate treatment and other adverse outcomes that may be more likely to occur when care is conducted virtually. New systems of care, and providers’ initial discomfort with them, could result in higher costs due to using more resources.

Last, patient safety in the tele-urgent care setting is particularly underexplored, with the identified literature providing little guidance. Importantly, 1 included European study had a large sample and examined numerous practice sites and practitioners.^36^ A key to that system’s success appears to be right-sizing care through a nurse-led triage enhanced by software systems followed by direct hand-off to practitioners for on-call treatment, in-person care, or emergency services. If any health care system in the United States is structured for centralized triage and in-network referral, it is the VA health care system.

## LIMITATIONS

Our review has several strengths, including a protocol-driven design, a comprehensive search, inclusion of broad observation and experimental designs, and careful quality assessment via established risk of bias tools. Both our review and the literature, however, have limitations. Overall, the number of identified studies for many outcomes was small, and most of the literature had design limitations that affected study quality. None of the studies that met eligibility criteria provided analysis by provider characteristics (ie, specialty, amount of telehealth experience, training), and studies did not provide sufficient information to conduct study-level subgroup analysis. There were insufficient studies to explore the role of tele-urgent care by mode (ie, telephone, video) for any outcome. As a result, we were unable to address the differential impact of tele-urgent care by these moderators. Other limitations are detailed below.

### Publication Bias

Given the small number of studies, statistical methods to detect publication bias are not useful. Other strategies, such as searching ClinicalTrials.gov for completed but unpublished studies, are not particularly effective ways to identify publication bias.^44^ Thus, we did not conduct formal publication bias analysis.

### Study Quality

We were also limited by the existing literature. We identified only 4 EPOC designs (2 RCTs and 2 controlled before-and after studies). The majority (n=8) were cross-sectional with many having significant ROB considerations. Inadequate measurement and adjustment for key confounding variables, section of sample; and missingness contributed to judgment of higher ROB across studies.

### Heterogeneity

Tele-urgent care is a complex health intervention, which has innate heterogeneity. This review included a wide variety of study designs across key questions. For KQ 1, our review also included 3 different comparisons across outcomes: (1) impact by organization of the tele-urgent service (local vs regional systems), (2) impact by urgent care venue (eg, tele-urgent care services vs in-person urgent care clinics), and triage decision of tele-urgent care (patient satisfaction only). We addressed this heterogeneity by clustering our narrative synthesis by outcome and then by comparison type. We gave more conceptual weight to higher quality designs.

### Applicability of Findings to the VA Population

None of the included studies were conducted in VHA or specifically with Veterans. However, we limited eligibility to studies conducted in OECD countries, which improves applicability to VHA. As stated above, many of the included studies were conducted in the United Kingdom, which improves the applicably to the VHA system. All included studies of costs, however, were conducted in the United States. The findings presented here likely have applicability to any large health care system, such as the VHA, seeking to implement tele-urgent care systems.

## RESEARCH GAPS/FUTURE RESEARCH

This comprehensive review of the literature identified several gaps in the current evidence that warrant future investigation. We used the framework recommended by Robinson et al to identify gaps in evidence and classify why these gaps exist (Table 9).^45^ This approach considers the population, intervention, comparator, outcome, timing, and setting (PICOTS) to identify gaps and classifies them as due to (1) low strength of evidence or imprecise information, (2) biased information, (3) inconsistency or unknown consistency, and (4) not the right information.

Table 9 Evidence Gaps and Future Research

Evidence Gap | Reason | Type of Studies to Consider
Population
- No studies that actively recruited Veterans | Insufficient information | - RCTs; - Quasi-experimental studies; - Prospective cohort studies
Interventions
- How do the effects of tele-urgent care differ by modality (eg, telephone vs video)?; - What type of type and amount of provider training and experience maximizes quality and minimizes costs?; - Is provider oversight sufficient or do providers have to conduct the tele-urgent care consultation?; - What impact does access to the electronic medical record have on tele-urgent care?; - Does tele-urgent care staff experience (eg, years conducting remote triage) matter more than staff type (eg, MD or RN)?; - How do expectations of tele-urgent care services influence overall patient satisfaction?; - What are the most important elements of patient satisfaction with tele-urgent care (eg, overall satisfaction, satisfaction with triage decisions)? | Insufficient information | - Comparative effectiveness trials of different types of interventions; - Dismantling studies; - Longitudinal studies; - Qualitative studies
Comparators
- Few head-to-head comparisons of different modalities; - No head-to-head comparisons of different staff types by training and level of experience | Insufficient information | - Cluster RCTs; - Comparative effectiveness trials
Outcomes
Limited information on:; - Health care utilization; - Patient satisfaction; - Costs; - Health care access; - Case resolution; - Patient safety; - Adverse effects | Insufficient information | - Cluster RCTs; - Prospective cohort studies; - Nonrandomized controlled before-and-after studies
Setting
- Limited evidence from US setting, VA Health Care System | Insufficient information | - Cluster RCTs; - Hybrid implementation designs; - Prospective or retrospective cohort studies; - Nonrandomized controlled before-and-after studies

## CONCLUSIONS

In early 2020, as telehealth utilization increased, health care providers, patients, and health care organizations rapidly increased their appreciation for care delivered virtually. Rates of patient “no-shows” ^46^ and travel expenses and travel time decreased,^47^ and health care access and scheduling was eased for many, including those with low income.^9^ Early in the COVID-19 pandemic, telehealth visits increased 154%,^10^ and subsequent data showed substantial decreases in ED visits.^11^ Additionally, 76% of patients now view telehealth services favorably, compared to only 11% in 2019, and 58% of health care providers view telehealth more favorably now than before the COVID-19 pandemic.^12^

The promise of tele-urgent care is to improve access to timely health care for low-acuity conditions.^39^ Yet there are many unanswered questions about the effects of tele-urgent care on key clinical and health systems outcomes, including costs. Our review provides evidence that tele-urgent care may not significantly increase subsequent utilization of health care services compared to in-person non-ED urgent care. Still, some limited evidence supports that the introduction of tele-urgent care increases overall health care utilization in a system via enhanced access to a convenient source of on-demand care. System leaders need to be attentive to both the intended and unintended consequences of incorporating tele-urgent care in the delivery of health services. Further examination is needed to assess whether and how tele-urgent care can be used to support efforts to attain the quadruple aim^48^ of improving the patient care experience, improving the health of a population, reducing per capita health care costs, and improving the work life of health care providers, including clinicians and staff. As we explore the value of tele-urgent care, it will be critical to weigh potential benefits against both financial costs for the health care system and human costs for increased and varying staffing demands.