# RESULTS

## LITERATURE FLOW

We identified 6,474 studies through searches of MEDLINE (via Ovid), EMBASE, and CINAHL (via EBSCO) (Figure 2). An additional 5 articles were identified through reviewing bibliographies of relevant review articles for a total of 6,479 articles. After removing duplicates, there were 4,311 articles in total. After applying inclusion and exclusion criteria to titles and abstracts, 221 articles remained for full-text review. Of these, 17 studies were retained for data abstraction. Of the 17 studies included, 16 were identified as unique studies. There were 13 unique studies included for KQ 1 and 3 studies for KQ 2. They consisted of 1 randomized controlled trial, 1 cluster-randomized trial, 2 controlled before-after studies, 8 cross-sectionals, and 4 cohorts. Included studies were conducted across North America and Europe (USA, UK, and Ireland). None of the studies were conducted in the VA.

Figure 2 Literature Flowchart

^a^ Search results from Medline (1,830), Embase (791), CINAHL (1,685), and manually identified (4) were combined.

## EVIDENCE PROFILE

Table 2 shows the evidence profile of studies included in this systematic review.

Table 2 Evidence Profile for Studies of Tele-urgent Care for Low-acuity Conditions

Number of studies: 16 studies
Median number of participants: 8,764 (range 298 to 20.6 million)^a^
Regions: UK (n=9); USA (n=5); Ireland (n=1); Denmark (n=1)
Patient demographics: Median age = 36 years old (14 studies NR); 58% Women (6 studies NR); Race: 86% White, 14% Other (15 studies NR)
Intervention mode^b^: Telephone (n=13); Video (n=4); Internet (n=1); NR (n=1)
Comparisons^b^: In-person care (n=9); Provider type (n=2); NHS 111 (n=2); NA (n=3)
Outcomes reported^b^: Health care utilization (n=6); Patient satisfaction (n=7); Cost (n=4); Case resolution (n=2); Health care access (n=2); Patient safety (n=0); Adverse effects (n=3)
Risk of bias:
RoB 2: Low risk of bias (n=0); Some concerns (n=2); High risk of bias (n=0);
ROBINS-I: Low (n=0); Moderate (n=4); Serious (n=2); Critical (n=0); No information (n=0)
NIH quality assessment tool: Good (n=4); Fair (n=4); Poor (n=0)

Abbreviations. NA= Not applicable; NIH= National Institutes of Health; NHS=National Health System; NR= Not reported

a 5 studies reported number of calls or visits with more than 1 encounter possible per person

b More than 1 category possible per study

## KEY QUESTION 1

A. Among adults, what are the effects of tele-urgent care for low-acuity conditions on key clinical and health system outcomes (ie, utilization, patient satisfaction, cost, health care access, case resolution, patient safety)?
B. Do the effects of tele-urgent care for low-acuity conditions differ by (1) provider characteristics (ie, specialty, amount of telehealth experience, training) or (2) mode of delivery (ie, telephone, video, web, short message service)?

### Characteristics of Included Studies

Thirteen studies were included for KQ 1.^3,21–32^ Six reported health care utilization,^3,21–23,25,31^ 7 reported patient satisfaction,^22,24,26,27,29,30,32^ 4 reported cost,^3,21,23,25^ 2 reported health care access,^22,27^ and 2 reported case resolution. They consisted of 1 RCT,^22^ 2 controlled before-after studies,^24,31^ 7 cross-sectionals,^23,25,26,28^–^30,32^ and 3 cohorts.^3,21,27^ The sample size of studies ranged from 1,115 to 20.6 million with a median of 7,213 participants. The risk of bias (ROB) for the 1 RCT was rated as some concerns.^22^ Of the cross-sectional studies, 4 were rated as good^25,26,30,32^ and 3 were rated as fair ROB.^23,28,29^ Three of the cohort and controlled before and after studies were rated as moderate ROB^21,24,31^ and 2 were rated as serious.^3,27^

None of the studies that met KQ 1 eligibility criteria provided analysis by provider characteristics (ie, specialty, amount of telehealth experience, training), and studies did not provide sufficient information to conduct study-level subgroup analysis. There were insufficient studies to explore the role of tele-urgent care by mode (ie, telephone, video) for any outcome. As a result, we were unable to address KQ 1B.

### Effects of Tele-urgent Care on Health Care Utilization: Key Points

- In total, 6 studies assessed the impact of tele-urgent care on health care utilization. Most of these had at least moderate risk of bias (ROB) concerns.
- Results from 2 cohort studies suggest that the introduction of tele-urgent care increased overall health care utilization (ie, “new utilization”) that may not have been sought and accessed without tele-urgent care options.
- Four studies assessed subsequent health care utilization (eg, outpatient visits) after initial consultation from tele-urgent care. These studies were designed to address 2 different comparisons: (1) the impact by organization of the virtual care service and (2) the impact by initial site of care (eg, tele-urgent care services vs in-person urgent care clinics).
  ○ Subsequent outpatient utilization did not significantly differ whether the tele-urgent care was delivered locally or regionally; nor did it differ with different staffing (eg, nonclinical call handler, nurse vs general practitioner) for the triage portion of the tele-urgent care interaction.
  ○ When comparing the initial site of urgent care on subsequent health care utilization, no clear pattern emerged when comparing urgent care initially sought via virtual modes or other, in-person venues (eg, urgent care centers, retail health clinics) outside the ED.

### Detailed Findings

We sought to describe the effects of tele-urgent care for low-acuity conditions on subsequent patient care (received for the same condition) and on health care utilization. In total, 4 US-based studies^3,21,23,25^ and 2 UK-based studies^31,33^ assessed the impact of tele-urgent care on health care utilization. Of these 6 studies, 2 assessed the impact of tele-urgent care on overall patterns in health care utilization,^3,21^ 4 assessed outpatient care services,^23,25,31,33^ 3 assessed ED utilization,^23,25,31^ and 2 assessed inpatient utilization after initial urgent care consultation.^23,25^ These studies were designed to address 2 different comparisons: (1) impact by organization of the tele-urgent service (local vs regional systems) and (2) impact by urgent care venue (eg, tele-urgent care services vs in-person urgent care clinics). Most studies had some ROB concerns (Figures 3–6).

Next, we organize results by utilization outcome (eg, subsequent outpatient visits, subsequent hospitalizations) and then by comparison of interests (organization of tele-urgent care system or urgent care venue).

#### Effects on Overall Patterns in Health Care Utilization

Two studies explored the impact of introducing tele-urgent care on patterns of health care utilization for low-acuity conditions. One moderate ROB cohort study^21^ looked at data from 2011 to 2013 for 981 US state health plan enrollees who had a direct-to-consumer telehealth visit for low-acuity respiratory infections (tele-urgent care condition). These telehealth visits were matched to 1,962 enrollees served only by in-person care for the same condition in the same period of time. This study estimated the in-person care being replaced by tele-urgent care and the care that constituted “new utilization” by comparing the change in in-person physician and ED visits to the change in telehealth visits. By 2013, tele-urgent care accounted for 85 visits per year per 100 people. Of these 85 tele-urgent visits, 11.8% (95% CI −24 to 3) were estimated to be substitutions for care to a physician’s office or the ED, and 88.2% (95% CI 60 to 88 visits) were increased utilization (ie, “new utilization”) attributable to the introduction of tele-urgent care services.

An additional serious ROB cohort study assessed trends from 2008 to 2015 in use of in-person and telehealth acute care venues across 20.6 million visits for low-acuity conditions using claims data from a large US-based commercial health plan.^3^ Overall, there was a 140% increase in non-ED urgent visits for low-acuity conditions. Compared with in-person urgent care services, tele-urgent care experienced an overall increase in the proportion of total visits, with low-acuity diagnosis codes from 0 visits in 2008 to 6 visits in 2015 per 1,000 members. In contrast, retail clinic visits (−3.9%) and in-person urgent care center visits (−6.1%) experienced a decrease in the proportion of low-acuity visits—suggesting that much of the overall increase in urgent care may be attributable to the use of tele-urgent care services (Table 3).

#### Effects on Subsequent Outpatient Care Utilization

Four studies—1 RCT (rated as some concerns for ROB),^22,33^ 2 cross-sectional (1 fair ROB^23^; 1 good ROB^25^), and 1 moderate ROB controlled before-and-after study^31^—assessed the impact of tele-urgent care on subsequent use of outpatient care after the initial tele-urgent care visit. Two studies assessed the impact of 2 different organizational models of telephone-delivered care (local vs national or regional call centers) and found no statistically significant increase in subsequent outpatient care.^31,33^ The other 2 studies compared subsequent use of outpatient visits in the 21 days following an index visit between video-based urgent care and in-person urgent care venues.^23,25^ Both studies found that urgent care initiated via video had fewer subsequent outpatient visits than urgent care sought in the ED. Yet no clear pattern emerged when comparing video-based and in-person urgent care delivered through non-ED venues.

##### Comparison by Organizational Structure of Tele-urgent Care

One UK-based RCT (rated as some concerns for ROB) compared after-hours care provided by the patient’s own GP practice (n=49 practice physicians) to that provided by commercial external agencies delegated to cover care for GP practices (n=183 external physicians; tele-urgent care condition).^33^ After adjusting for age, sex, ethnic group, and access to a car, there were no significant differences in number of visits to primary care in the 2 weeks following tele-urgent care contact (46.5% vs 44.2%, p=0.299). A second study was a moderate ROB controlled before-and-after assessment of the implementation of an updated national health advice line in England staffed by nonclinical call handlers (referred to as “NHS 111”) that encompassed 277,163 calls over the 1-year pilot.^31^ Prior to the implementation of NHS 111, all areas in England had a 24-hour nurse-led telephone helpline called NHS Direct, which used an initial contact with a nonclinical call handler who then directed calls to a nurse triage staff either during the same call or via a call-back. NHS 111 differed from NHS Direct in that it was managed by nonclinical call handlers who used computerized decision support software (CDSS) to immediately triage incoming calls, avoiding call-backs and wait times, and had the ability to direct callers to the most appropriate service or offer self-management advice. Calls that may involve self-care advice or require referral to specialist services are transferred for clinical advice before a final disposition was reached. NHS 111 resulted in an average monthly increase of 2.5% visits in outpatient care that was not statistically significant (95% CI −3.5 to +8.5).

##### Comparison by Urgent Care Site: Virtual versus In-person Venues

Two cross-sectional studies (1 good ROB,^25^ 1 fair ROB^23^), both conducted in the United States, used similar methods to compare the subsequent use of outpatient visits in the 21 days following an index visit between video-based tele-urgent care and other in-person urgent care venues. The first study was conducted in an integrated health care system, Intermountain Health in Utah.^25^ This study compared claims for low-acuity urgent conditions across 1,531 video-based urgent care visits, 2,285 ED visits, 4,377 in-person urgent care center visits, and 4,388 in-person primary care visits. In the 21 days following the index visit, patients initially evaluated via video-based urgent care visits had a statistically significant increase in outpatient visits than those initially evaluated in primary care settings (4% more visits), but fewer primary care visits than those who were seen in the ED (13.2% fewer visits). Compared with video-delivered urgent care, initial care delivered at an in-person urgent care center had similar rates of outpatient visits after the index visit. The second study^23^ examined 59,945 on-demand visits for acute conditions (eg, colds, allergies, urinary tract infections). The analysis included 4,635 virtual online (ie, tele-urgent) and 55,310 non-virtual visits to retail health clinics, in-person urgent care centers, ED, or primary care physicians. The percentage of outpatient follow-up visits within 21 days of the index visit did not have a statistically significant difference between virtual video-delivered urgent care and care delivered via retail health clinics and primary care clinics. Both studies found that urgent care initiated via video had fewer subsequent outpatient visits than urgent care sought in the ED (Table 3).

#### Effects on Subsequent Emergency Department Utilization

Three studies—1 moderate ROB controlled before-and-after study^31^ and 2 cross-sectional studies (1 good ROB,^25^ 1fair ROB^23^)—assessed the impact of tele-urgent care on subsequent use of the ED. One study assessed the impact of nationalizing the delivery of tele-urgent care in the year after NHS 111 was piloted and found no statistically significant increase in subsequent ED utilization.^31^ The other 2 studies compared subsequent use of the ED in the 21 days following an index visit between video-based tele-urgent care and in-person urgent care venues.^23,25^ Again, results were inconsistent when comparing tele-urgent care with non-ED urgent care delivered in-person on subsequent ED use.

##### Comparison by Organizational Structure of Tele-urgent Care

The moderate ROB controlled before-and-after study (Turner et al, 2019, described above) that assessed the implementation of an updated national health consultation telephone service in England staffed by nonclinical call handlers in NHS 111 found no change in ED utilization in the year after NHS 111.^31^ Yet this study did find a statistically significant increase in ambulance services after in implementation of NHS 111 (Table 3.)

##### Comparison by Urgent Care Site: Virtual versus In-person Venues

The good ROB cross-sectional study conducted in an integrated health care system in the United States (Lovell et al, 2019, described above) compared low-acuity video-based tele-urgent care index visits with index visits originating at the ED, in-person urgent care, or in-person primary care setting.^25^ There were no significant differences in follow-up rates of subsequent ED visits between tele-urgent care and both in-person urgent and in-person primary care in the 21 days following the index visit. Yet patients initially evaluated via tele-urgent care had a statistically significant decrease in follow-up visits to the ED compared with those initially evaluated in the ED (7.9% fewer visits). The fair ROB cross-sectional study (Gordon et al, 2017; described above) also found that the urgent care delivered by video consultation resulted in a statistically significant decrease in subsequent ED visits in the 21 days after index visit compared to urgent care initially delivered at the ED (5.3% decrease).^23^ This study also found that video-delivered urgent care had fewer subsequent ED visits than low-acuity urgent care initiated in primary care clinics (0.5% decrease) or in-person urgent care (1.4% increase) and similar rates of acute care delivered via retail health clinics.^23^

#### Effects on Hospitalizations

##### Comparison by Urgent Care Site: Virtual versus In-person Venues

Two US-based cross-sectional studies (1 good ROB^25^ and 1 fair ROB^23^) assessed the impact of urgent care venue on subsequent rates of hospitalization. Both studies found that urgent care delivered by video resulted in a statistically significant decrease in subsequent hospitalizations 21 days after the index visit compared with care delivered at the ED (range 2.2% to 5.2%). Yet no significant differences were reported in the number of hospital stays comparing tele-urgent care with in-person urgent care and in-person primary care in the good ROB study.^25^ In comparison, the fair ROB study found that tele-urgent care had a statistically significant decrease in hospitalizations compared with in-person primary care and in-person urgent care (0.2% fewer visits for both settings) and similar rates for acute care delivered via retail health clinics.^23^

Table 3 Summary of Effects of Tele-urgent Care on Type of Health Care Utilization Pattern

Study | Outcome Description | Results
Overall Patterns in Health Care Utilization
Poon, 2018^3^ | Proportion of total visits with low-acuity diagnosis codes by venue | Tele-urgent care via video; Percent of visits in 2008: not able to be computed; Percent of visits in 2015: 68%; In-person urgent care; Percent of visits in 2008: 71.5%; Percent of visits in 2015: 65.4%; Retail clinics; Percent of visits in 2008: 61.8%; Percent of visits in 2015: 57.9%; Emergency department; Percent of visits in 2008: 38.4%; Percent of visits in 2015: 28.8%
Ashwood, 2017^21^ | Substitution of tele-urgent care for in-person health care utilization: decrease in non-telehealth visits to the increase in telehealth visits between telehealth user and nonusers in physician office or emergency department visits for acute respiratory infections (per 100 persons per year) | Between-group differences in physician office visits or emergency department use between telehealth users and nonusers; -10 visits (95% CI −24 to 3)
Ashwood, 2017^21^ | New health care utilization attributable to tele-urgent care: change in total number of telehealth visits and those estimated to be substituting for in-person visits for acute respiratory infections (per 100 persons per year) | Between-group differences for all sites in physician office visits or emergency department use between telehealth users and nonusers; +74 visits (95% CI 60 to 88)
Outpatient Care Utilization: Comparison by Organizational Structure of Tele-urgent Care
McKinley, 1997^33^ | Percent of patients seen in general practice by doctor or nurse in 2 weeks after out of hours call | Practice physicians providing tele-urgent care; 46.5%; Tele-urgent care by physicians outside patients’ practice; 44.2%; p = 0.299
Turner, 2013^31^ | Percent change in monthly activity counts for GP out-of-hours, walk-in clinics, minor injury unit, urgent care centers attendance between new telephone-based urgent care (NHS 111) pilot and control sites | Estimated percent change in monthly activity between tele-urgent care pilot sites and control sites; +2.5% (95% CI −3.5% to 8.5%)
Outpatient Care Utilization: Comparison by Virtual versus In-person Venues
Lovell, 2019^25^ | Percent with outpatient clinic visit within 21 days | In-person urgent care vs video-based urgent care; 0.92 relative ratio (95% CI 0.83 to 1.01); Primary care vs video-based urgent care; 0.85 relative ratio (95% CI 0.77 to 0.93); Emergency department care vs video-based urgent care; 1.50 relative ratio (95% CI 1.35 to 1.64)
Gordon, 2017^23^ | Percent of patients with all-cause outpatient visit during 3-week episode post-index visit | In-person urgent care centers vs video-based urgent care; 25.6% vs 28.1% (p = 0.001); Primary care physicians vs video-based urgent care; 28.1% vs 28.1% (p = 0.99); Retail health clinics vs video-based urgent care; 28.6% vs 28.1% (p = 0.51); Emergency department vs video-based urgent care; 34.2% vs 28.1% (p <0.001)
Emergency Services Utilization: Comparison by Organizational Structure of Tele-urgent Care
Turner, 2013^31^ | Percent change in monthly ED visits in new telephone-based urgent care (NHS 111) pilot sites compared to control sites | Estimated percent change in monthly activity between pilot sites and control sites; −0.1% (95% CI −3.8% to 3.7%)
Turner, 2013^31^ | Percent change in monthly utilization of ambulance services (defined as arriving at incident scene) between new telephone-based urgent care (NHS 111) pilot sites compared to control sites | Estimated percent change in monthly activity between pilot sites and control sites; +2.9% (95% CI 1.0 to 4.8%)
Emergency Department Utilization: Comparison by Virtual versus In-person Venues
Lovell, 2019^25^ | Percent with emergency department visit within 21 days by index visit site for urgent care | In-person urgent care vs video-based urgent care; 1.29 relative ratio (95% CI 0.75 to 1.83); Primary care vs video-based urgent care; 1.49 relative ratio (95% CI 0.87 to 2.12); Emergency department care vs video-based urgent care; 5.53 relative ratio (95% CI 3.34 to 7.71)
Gordon, 2017^23^ | Percent of patients with all-cause emergency department visits during 3-week episode post urgent care index visit | In-person urgent care centers vs video-based urgent care; 2.7% vs 1.3% (p <0.001); Primary care physicians vs video-based urgent care; 1.8% vs 1.3% (p = 0.02); Retail health clinics vs video-based urgent care; 1.6% vs 1.3% (p = 0.16); Emergency departments vs video-based urgent care; 6.5% vs 1.3% (p <0.001)
Hospitalizations: Comparison by Virtual versus In-person Venues
Lovell, 2019^25^ | Percent with inpatient admission within 21 days by index visit site for urgent care | In-person urgent care vs video-based urgent care; 1.57 relative ratio (95% CI 0.19 to 2.94); Primary care vs video-based urgent care; 1.77 relative ratio (95% CI 0.22 to 3.32); Emergency department care vs video-based urgent care; 6.74 relative ratio (95% CI 1.11 to 12.36)
Gordon, 2017^23^ | Percent of patients with all-cause inpatient visit during 3-week episode post-index visit | In-person urgent care centers vs video-based urgent care; 0.4% vs 0.2% (p = 0.01); Primary care physician vs video-based urgent care; 0.4% 0.2% vs (p = 0.02); Retail health clinic vs video-based urgent care; 0.3% vs 0.2% (p = 0.12); Emergency department vs video-based urgent care; 1.0% vs 0.2% (p <0.001)

### Effects of Tele-urgent Care on Patient Satisfaction: Key Points

- Seven studies reported on patient satisfaction with tele-urgent care. All 7 were conducted in European medical systems where out-of-hours urgent care is typically provided as part of a broad, integrated system. In such systems, telephone triage could be followed by telephone consultation for self-care, by a recommendation for an in-person visit to a physician or in-person urgent care center, or by a physician home visit.
- Overall, patients expressed the greatest satisfaction when the care they received matched their expectations for care.
- Differences in patient satisfaction were not consistently observed by triage decision of tele-urgent care interaction (telephone vs clinic visit vs home visit) or by organizational structure of the telephone-delivered care (external physicians vs practice-based and/or cooperative physicians). When differences in satisfaction were observed among triage decision, telephone was found to be associated with lower patient satisfaction compared to in-person care.

### Detailed Findings

All 7 studies that evaluated the effects of tele-urgent care on patient satisfaction were conducted in European medical systems where out-of-hours care is typically provided as part of a broad, integrated system.^24,26,27,29,30,32,33^ In such systems, telephone care could be followed by telephone consultation for self-care, by a recommendation for an in-person visit to a physician or in-person care center, or by a physician home visit. In this context, 3 studies examined the impact of tele-urgent care triage decision (telephone advice for self-care vs home visit or in-person treatment at a center),^26,30,32^ and 4 examined the effects of the organizational structure of telephone-delivered urgent care system (ie, local practice-based service vs national or regional “deputizing” call centers)^24,27,29,33^ on satisfaction among patients seeking tele-urgent care. Of these 7 studies, 1 was a randomized controlled trial,^33^ 1 was a cohort,^27^ 1 was a controlled before-and-after study^24^, and 4 were cross-sectional studies.^26,29,30,32^ Only 1 study had serious ROB concerns.^27^ All other studies were assessed as having no serious ROB concerns. Overall, patients expressed the greatest satisfaction when the care they received matched their expectations for care; patients expressed the greatest dissatisfaction when the care they received did not match their expected care. Differences in patient satisfaction were not consistently observed by triage decision of tele-urgent care interaction (ie, telephone advice for self-care vs clinic visit vs home visit) or by organization (ie, external “deputizing” physicians vs practice-based and/or cooperative physicians). When differences in satisfaction were observed among triage decision, telephone advice was found to be associated with lower patient satisfaction compared with in-person care.

#### Comparison by Triage Decision of Tele-urgent Care

Two good ROB cross-sectional studies specifically compared dissatisfaction among patients seeking tele-urgent care who were triaged to receive telephone consultation for self-care, visit a clinic, or receive a home visit.^30,32^ The first study evaluated patients calling the Glasgow Emergency Medical Service (GEMS).^32^ A total of 1,115 patients responded to a survey mailed to every other caller 1 week after contact with the service. Most patients in this study received either a home visit (23%) or visited a clinic (55.9%), while 13.1% received telephone advice only. The authors found that among the variables examined (age, gender, socioeconomic status, perceived difficulty with daytime service, perceived urgency of complaint, match between service expected and service received), patient dissatisfaction was most strongly associated with a disjunct between patients’ expectation and the actual triage decision they received. Patients who expected a home visit but received telephone advice expressed the most dissatisfaction with tele-urgent care, followed by those who expected to be invited to attend a center but received telephone advice, and finally by those who expected to receive a home visit but were asked to attend a center. The second study compared dissatisfaction among 7,213 patients who responded to a postal survey after calling for out-of-hours urgent care in Denmark and being triaged by a physician to receive either a telephone consultation for self-care, a clinic consultation, or a home visit.^30^ While the majority of patients reported satisfaction with their experience, patients who received telephone advice for self-care were significantly more likely to report dissatisfaction than those who received either a clinic consultation or a home visit, particularly for those living in urban compared with rural areas.

A third cross-sectional study specifically evaluated whether patient expectations interacted with the care they received to predict satisfaction.^26^ Patients requesting out-of-hours care were mailed questionnaires the day after making contact, and 2,263 surveys were returned. A regression model included the type of care (telephone advice, visit to center, or home visit), the type of telephone-based after-hours service (practice-based physician, physician cooperative, or external physician deputizing service), whether or not the service received was the service that was hoped for, and the subscales of the satisfaction scale. Results of the regression indicated that patients who received the type of care they hoped for were likely to report greater satisfaction with tele-urgent care. Also, patients were more satisfied with tele-urgent care from the physician cooperative than the external physician deputizing service. While telephone advice was not significantly different from receiving a home visit in this model, patients who received telephone advice for self-care reported the lowest rate of having received the care they hoped for across types of telephone-based after-hours service (ie, practice-based physician, physician cooperative, or external physician deputizing service).

#### Comparison by Organizational Structure of Tele-urgent Care

Three studies explored the impact of receiving after-hours care from a physician in their own practice compared with those receiving care from GP cooperatives or physicians through commercial external agencies delegated to cover care for GP practices (referred to as “deputizing” service).^27,29,33^ The first study was an RCT (rated as some ROB concerns) that evaluated differences in satisfaction between patients in the UK who received care from a physician in their own practice compared with a GP deputizing service. A total of 2,152 patients were interviewed by phone between 24 and 120 hours after contacting the out-of-hours service for care using a questionnaire developed and validated by one of the study authors.^33^ Results indicated patients expressed significantly higher satisfaction with practice doctors compared with deputizing service doctors,^33^ even though practice doctors were much more likely to give telephone advice than deputizing doctors (20.8% vs 1.5%, respectively).^33^

Two studies assessed the impact of out-of-hours telephone-based urgent care delivered by local practice-based physicians compared to physician cooperatives and/or commercial deputizing physician services. Both found no significant differences in patient satisfaction by organization of tele-urgent care service. The first study was a cohort study with serious ROB considerations. Patients were sent a survey within 7 days of their interaction with either deputizing service or practice-based service.^27^ While in bivariate analyses of the 1,555 responses they found that overall satisfaction was higher for physician cooperative than commercial deputizing external physician service, in a multiple regression this variable was no longer significant. Rather, the following variables were each negatively associated with overall satisfaction: receiving telephone advice, having a preference for seeing one’s own doctor, and wanting to receive a home visit compared with wanting to attend a center or receive telephone advice. The second study replicated the methods of the Salisbury et al study, with surveys mailed 1 week after contact to a random sampling of patients seeking out-of-hours care in London stratified by organization of after-hours care (ie, local practice-based vs GP cooperative vs deputizing external physician service).^29^ Results indicated that satisfaction did not differ between the GP cooperative, the practice-based arrangement, or the commercial deputizing physician service.

One additional study assessed the organization of tele-urgent care on patient satisfaction before and after transition to a new national telephone-based service in the UK (ie, NHS 111).^24^ This study was a moderate ROB controlled before-and-after study using a validated telephone-administered questionnaire to examine patient satisfaction in pilot and control areas of the UK before and after the transition from NHS Direct to NHS 111. NHS Direct was a 24-hour nurse-led telephone help line that provided 24-hour service and that also handled out-of-hours calls for some general practices. NHS Direct did not have direct access to prescribers or to appointments, though nurses would advise people to call their local physician’s out-of-hours service. While most NHS 111 calls are handled by nonclinical call handlers, this service is linked in with the out-of-hours physician practices and can offer telephone consultations by a prescriber, home visits, and face-to-face reviews on site. As such, the transition from NHS Direct could be examined in the context of a transition from a nurse-led advice line to a model that more closely maps to the definition of tele-urgent care. Of the 28,071 respondents, 2,237 reported having used urgent care (NHS Direct/“control” or NHS 111/“pilot”) within the prior 3 months and were therefore included in the analyses. Results indicated no significant change in patient satisfaction with tele-urgent care experience before and after transitions to NHS 111.

Table 4 presents a summary of the effects of different aspects of tele-urgent care on patient satisfaction outcomes reported in the included studies.

Table 4 Summary of Effects of Tele-urgent Care on Patient Satisfaction

Study | Comparison | Assessment Scale | Results
Comparison by Triage Decision of Tele-urgent Care
Tranberg, 2018^30^; Cross-sectional; N=7213 patients | Satisfaction with telephone consultation vs clinic consultation vs home visit | “Overall satisfaction with the contact” item included in broader questionnaire, with 6 response items: “Very satisfied,” “satisfied,” “dissatisfied,” “very dissatisfied,” “neutral,” and “don’t know”; “neutral” and “don’t know” were excluded, and “dissatisfied” and “very dissatisfied” were combined in analysis | - More patients were dissatisfied (p <0.001) with telephone (8.5%) vs clinic consultation (6.0%) or home visit (4.3%); - Dissatisfaction was most strongly associated with “unacceptable wait time”
Wilson, 2001^32^; Cross-sectional; N=1115 patients | Dissatisfaction for receiving home visit vs attend a center vs telephone advice | Unvalidated 5-point scale of agreement with statement that completely satisfied with type of contact received, from “strongly agree” to “strongly disagree” | - Odds of patient dissatisfaction were most strongly related to expectations and outcome (p <0.0001); - Dissatisfaction was expressed by patients expecting to attend a center but receiving telephone advice (OR 6.43, 95% CI 3.35 to 12.32, p <0.0001); - Dissatisfaction was expressed by patients who expected home visit but were asked to attend a center (OR 5.48, 95% CI 3.30 to 9.09, p <0.0001); - Dissatisfaction was expressed by 35% expecting a home visit but receiving telephone advice (OR 10.55, 95% CI 5.70 to 19.53, p <0.0001)
McKinley, 2002^26^; Cross-sectional; N=2263 patients | Satisfaction with home visit vs attend center vs telephone | Scale developed and validated by McKinley,^34^ modified by Salisbury,^27^ with 2 additional items added; 5-point scale for overall agreement with statement of satisfaction, with 5 as strongest agreement, 3 as neutral, 2 as strongest disagreement | - Patients who received the type of care they hoped for in terms of service type and consultation type were significantly more satisfied than those who did not, β=230.4, SE(β)=52.8, p <0.0001; - Greater satisfaction was associated with center attendance vs home visits, β=161.4, SE(β)=79.7, p=0.04; - Greater satisfaction was associated with cooperative vs deputizing service, β=272.6, SE(β)=120.1, p=0.02
Comparison by Organizational Structure of Tele-urgent Care
McKinley, 1997^33^; (Companion: Cragg, 1997)^22^ | Deputizing service physicians vs practice-based physicians | Patient Satisfaction Questionnaire developed and validated by McKinley^34^: range 0 to 100%, with higher scores reflecting greater satisfaction | Patient satisfaction, mean: 61.8% (95% CI 59.9 to 63.7) deputizing service vs 70.7% (95% CI 68.1 to 73.2) practice doctors p <0.0001
Salisbury, 1997^27^; Cross-sectional; N=1555 contacts (visits) | GP cooperative vs deputizing service physicians | Scale developed and validated by McKinley,^34^ modified by Salisbury,^27^ 5-point scale for overall agreement with statement of satisfaction, with 5 as strongest agreement, 3 as neutral, 2 as strongest disagreement | - Overall satisfaction higher for GP cooperative than deputizing service (mean difference [SE] = −0.12[0.06], p=0.041); - In multiple regression the variable cooperative vs deputizing service was no longer significant, but the following variables were negatively associated with overall satisfaction:; ○ Preference for seeing one’s own doctor (mean (SE) regression estimate = −0.461 (0.055), p <0.001); ○ Receiving telephone advice (mean (SE) regression estimate = −0.431(0.069), p <0.001); - Wanting to receive a home visit vs to receive telephone advice or attend primary center (mean [SE] regression estimate = −0.489 [0.060] p<0.001)
Shipman, 2000^29^ | GP cooperative vs practice-based arrangement vs deputizing service | Scale developed and validated by McKinley,^34^ modified by Salisbury,^27^ 5-point scale for overall agreement with statement of satisfaction, with 5 as strongest agreement, 3 as neutral, 2 as strongest disagreement | - Mean overall satisfaction scores did not differ between GP cooperative (3.26; 95% CI 3.16 to 3.36) or practice-based arrangement (3030; 95% CI 316 to 3.43) or deputizing service (3.17; 95% CI3.05 to 3.28); p value not reported
Knowles, 2016^24^ | Before and after transition to new national telephone-based service in the UK (ie, NHS 111) | Validated “Urgent Care System Questionnaire,” a 5-point scale for overall satisfaction from “poor or very poor” to “excellent,” dichotomized to reflect “excellent” vs all others | Comparison between pilot and control regions of pre-intervention to post-intervention change in proportion of “excellent” rating of urgent care services: OR 0.97 (95% CI 0.69 to 1.37)

### Effects of Tele-urgent Care on Health Care Cost: Key Points

- Four studies assessed the cost of delivering tele-urgent care; all were conducted in the United States. All but 1 cross-sectional study was judged to have moderate to serious ROB considerations.
- Across included studies, index costs and total costs for care associated with tele-urgent visits for low-acuity conditions were lower for tele-urgent-type visits compared with similar types of visits for in-person settings (eg, ED, in-person urgent care centers). Yet 1 study supports that tele-urgent care may increase overall health care spending via increased access to on-demand care for low-acuity conditions.
- There was variability in how cost was estimated, making it difficult to compare across studies.

### Detailed Findings

In total, 4 US-based studies assessed costs for urgent visits for low-acuity conditions by virtual or in-person venues. Three studies assessed the costs of the initial urgent care visit (ie, index costs): 2 cross-sectional studies (1 fair ROB^23^; 1 good ROB^25^) and 1 serious ROB cohort study ^3^). Three studies also reported on total costs associated with urgent care by virtual or in-person venue: 2 cross-sectional studies (1 fair ROB^23^; 1 good ROB^25^) and 1 moderate ROB cohort study.^21^ For this review, index costs are defined as the cost of only the initial tele-urgent care visit, with no additional costs for subsequent care resulting from the visit. Total cost calculations included the index costs plus additional costs from follow-up care such as medications or testing (eg, imaging, bloodwork). Overall, with the exception of 1 instance where the total annual spending was moderately increased for tele-urgent care users over nonusers,^21^ index costs and total costs across studies were lower for tele-urgent-type visits compared with other settings. Of note, the computed index visit costs for tele-urgent care were similar for all 3 studies: $45,^25^ $49,^23^ and $39-$40.^3^ Total costs across studies by site of urgent care had more variability, likely due to inconsistent inclusion of laboratory, imaging, and pharmacy costs. Yet 1 study demonstrated that net annual health care costs for low-acuity conditions (ie, respiratory illnesses) increased $45 per tele-urgent care user compared with nonusers.

Next, we organize studies by index costs and then by total costs. A summary of results is shown in Table 5.

#### Effects of Tele-urgent Care on Index Cost

A good ROB cross-sectional study examined 59,945 on-demand visits for acute conditions (eg, colds, allergies, urinary tract infections).^23^ This analysis included 4,635 video-based urgent care visits and 55,310 non-virtual visits. When accounting for the costs of the index visit only, video-based urgent care had a statistically significant lower cost than in-person retail clinic, urgent care centers, primary care clinic, and ED visits. Another fair ROB study, also cross-sectional, included 1,531 claims for video-based visits for low-acuity urgent conditions with 2,285 ED visits, 4,377 in-person urgent care visits, and 4,388 in-person primary care visits.^25^ This study also found that index visits for on-demand acute conditions had a statistically significant greater cost at in-person venues compared with video-based urgent care visits. Both studies also reported the largest cost differences between video-based urgent care and ED visits ($1,339 to $1,355 more per visit for the ED).

One additional serious ROB cohort study examined 20.6 million in-person and telehealth acute care visits for treatment of low-acuity conditions at 2 time points, baseline and 8 years’ follow-up.^3^ This study also reported that the index cost for tele-urgent care was lower than in-person urgent care delivered via the ED, in-person urgent care centers, and retail clinics. Over the 8-year follow-up, index costs remained relatively stable for in-person urgent care ($165 to $162), retail clinic ($74 to $75), and tele-urgent care ($40 to $39). Yet the price per ED visit for a low-acuity condition increased by 79%, from $914 per visit in 2008 to $1,637 per visit in 2015.

#### Effects of Tele-urgent Care on Total Cost

A cross-sectional study described above examined 4,635 virtual (ie, tele-urgent) and 55,310 non-virtual visits. Retail clinic, urgent care, ED, and primary care provider visit costs were estimated to be $36, $153, $1,735, and $162 (respectively) more costly than virtual tele-urgent care visits in a 3-week episode, inclusive of pharmacy and subsequent medical visit costs.^23^ Another cross-sectional study considered costs of 1,531 virtual visits for low-acuity urgent conditions with 2,285 ED visits, 4,377 in-person urgent care visits, and 4,388 in-person primary care visits.^25^ The virtual visit average cost ($428) was significantly lower than in-person visits at urgent care ($661), primary care ($706), and ED ($3,403), including laboratory and imaging services, index visit cost, and total cost over a 21-day period.

One moderate ROB cohort study looked at 2012–2013 data for 981 state health plan enrollees who had a telehealth visit for low-acuity respiratory infections (tele-urgent care condition), matching those to 1,962 enrollees served by a different care setting in the same period of time.^21^ While telehealth users increased annual spending by $45 (95% CI $10 to $79) compared with nonusers per person, the total average spending per episode was less for a telehealth visit ($79) compared with a physician office visit ($146) or an ED visit ($1,734). In this study, total cost included the evaluation and management coding the day of the visit and the evaluation and management coding of follow-up visits plus costs related to pharmacy, imaging, and testing.

Table 5 Summary of Effects of Tele-urgent Care on Health Care Cost

Study | Outcome Description | Results
Index Cost
Gordon, 2017^23^ | Mean index visit cost | Video-based urgent care; Mean cost: $49; Retail health clinic; Mean cost: $74; Relative ratio: 1.52 (95% CI 1.49 to 1.54); In-person urgent care; Mean cost: $134; Relative ratio: 2.75 (95% CI 2.70 to 2.79); In-person primary care; Mean cost: $109; Relative ratio: 2.25 (95% CI 2.21 to 2.28); Emergency department; Mean cost: $1404; Relative ratio: 28.87 (95% CI 28.39 to 29.36)
Lovell, 2019^25^ | Mean index visit cost | Video-based urgent care; Mean cost: $45.0; In-person urgent care:; Mean cost: $135.7; Relative ratio: 3.01 (95% CI 2.92 to 3.10); In-person primary care; Mean cost: $114.4; Relative ratio: 2.54 (95% CI 2.46 to 2.62); Emergency department; Mean cost: $1,383.9; Relative ratio: 30.74 (95% CI 29.67 to 31.81)
Poon, 2018^3^ | Inflation-adjusted average prices per index visit (per person per year) | Tele-urgent care via video; Mean cost in 2008: $40; Mean cost in 2015: $39; In-person urgent Care; Mean cost in 2008: $165; Mean cost in 2015: $162; Retail clinics; Mean cost in 2008: $74; Mean cost in 2015: $75; Emergency department; Mean cost in 2008: $914; Mean cost in 2015: $1,637
Total Cost
Gordon, 2017^23^ | Index visit costs plus any follow-up cost of pharmacy and subsequent medical visit costs during 3-week episode post-index visit | Video-based urgent care; Mean cost: $339; In-person urgent care clinic; Mean cost: $492; Relative ratio: 1.45 (95% CI NR); Retail health clinic; Mean cost: $375; Relative ratio: 1.11 (95% CI NR); Primary care clinic; Mean cost: $501; Relative ratio: 1.48 (95% CI NR); Emergency department; Mean cost: $2,074; Relative ratio: 6.12 (95% CI NR)
Lovell, 2019^25^ | Index cost plus all following medical visits, prescriptions, laboratory tests, and imaging within the 21 days of index visit | Video-based urgent care; Mean cost: $428.9; Primary care; Mean cost: $706.6; Relative ratio: 1.65 (95% CI 1.26 to 2.04); Urgent care; Mean cost: $661.4; Relative ratio: 1.54 (95% CI 1.18 to 1.91); Emergency department; Mean cost: $3,403.0; Relative ratio: 7.93 (95% CI 5.78 to 10.09)
Ashwood, 2017^21^ | Index visit plus evaluation and management coding the day of the visit, the evaluation and management coding follow-up plus costs related to pharmacy, imaging, and testing | Tele-health users (ie, tele-urgent care); $79 (95% CI $75 to $86); Physician office; $146 (95% CI $140 to $150); Emergency department; $1,734 (95% CI $1,447 to $2,021)

### Effects of Tele-urgent Care on Health Care Access: Key Point

- Limited evidence was identified on the effects of tele-urgent care on access to health care. In a single study, patients’ satisfaction with the timeliness (ie, wait time) for telephone advice did not differ by organizational structure of telephone-delivered urgent care (external “deputizing” physicians vs local cooperative physicians).

### Detailed Findings

#### Timeliness

We aligned our concept of health care access with that of the US Office of Disease Prevention and Health Promotion’s Healthy People 2020 objectives^35^ and defined access as the ability to provide health care when the need is recognized (ie, timeliness) and satisfaction with provider services and communication (ie, services). We identified only 1 serious ROB cohort study that reported on timeliness of health care access measured as satisfaction with wait times.^27^ This study compared 2 different models of telephone-delivered consultation serving an overlapping area in London, England. Patients were sent a survey within 7 days of their interaction with either a commercial deputizing physician service (ie, tele-urgent care) or a local GP cooperative service.^27^ In a sub-analysis of patients who only received telephone advice for self-care, satisfaction with wait times for telephone advice did not differ between patients interacting with a GP cooperative physician (n=595) or an external commercial physician service (n=93) (Table 6).

#### Services

One RCT reported on patient satisfaction with the communication of the GP or the deputizing doctor.^22^ Patients were slightly more satisfied with the communication provided by the practice GP, with a mean satisfaction score of 68.9 (95% CI 66.5 to 71.4), compared to the deputizing physician who did not have a prior relationship with the patient, with a mean satisfaction score of 62.9 (95% CI 61.1 to 64.7). However, the p value for the difference in between these groups is significant (p = 0.0002).

Table 6 Summary of Effects of Tele-urgent Care on Health Care Access

Study | Outcome Description | Results
Timeliness
Salisbury, 1997^27^ | Patients’ satisfaction with wait time for telephone advice only | Telephone advice by cooperative physician; Weighted mean score: 3.26 (95% CI 3.10 to 3.42); Telephone advice by deputizing service; Weighted mean score: 3.29 (95% CI 3.17 to 3.40); Adjusted mean regression estimate; 0.08 (SE 0.11) p = 0.457
Services
Cragg, 1997^22^ | Satisfaction with provider communication | Practice doctors; Mean score 68.9 (95% CI 66.5 to 71.4); Deputizing doctors; Mean score 62.9 (95% CI 61.1 to 64.7); p = 0.0002

### Effects of Tele-urgent Care on Case Resolution: Key Points

- Evidence from 1 study suggested that local, practice-based telephone triage services have higher case resolution outcomes and refer fewer patients to emergency or primary care services compared with regional/national telephone-based urgent care services.
- Adding additional review of calls to telephone-based urgent care services originally triaged to the ED by either a physician advisor or a non-physician clinical advisor produced more case resolution on the first contact than calls assessed by a non-clinical call handler.

### Detailed Findings

Two studies reported on case resolution (ie, the health issue or concern was resolved during initial contact with the tele-urgent care system).^22,28^ Both studies were conducted in the UK and assessed different ways to organize tele-urgent care. In these studies, people who contacted remote triage services received 1 of 3 possible resolutions to their call: they were triaged to either emergency services, primary care services (including urgent care visits, home visits, or primary care clinic visits whether after-hours, the same day, or on a future date), or they achieved resolution of their health concern during the initial contact. Table 7 summarizes the results of these studies by these 3 groupings of case resolution status.

The first study, with an overall ROB rating of some concerns, was an RCT and compared a commercial deputized physician group (ie, tele-urgent care) versus local practice physicians.^22^ Deputizing physicians resolved only 1.4% of calls in the initial contact compared to 20.8% in the practice physician arm. Practice physicians also triaged fewer calls to a home visit (74.9% vs 94.8%) or the ED (0.4% vs 1.3%) than did deputizing doctors.

The next study was a fair ROB interrupted time series study that described the impact of an enhanced clinical assessment service to a national tele-urgent care service (ie, NHS 111).^28^ During the intervention period, callers who would have been triaged to ED attendance by non-clinical call handlers were immediately transferred to either an emergency physician (ie, tele-urgent care condition) or a non-physician clinical advisor (ie, nurses or paramedics with a scope of practice that includes assessment, treatment, advice, and diagnosis). Evaluation over the telephone by either of these clinician types reduced the number of callers sent to the ED (75% by physicians or 81% by a non-physician clinical advisor). There was a 22.4% (95% CI 19.0% to 25.7%) difference in the number of cases resolved through on-call advice for self-care between the physician advisors (38.1%) and the non-physician clinical advisor (15.7%). Of the cases resolved by in-person care, physician advisors triaged fewer people to out-of-hours GP clinics but more to the minor injuries units or walk-in centers or in-hours GP clinics than the non-physician clinical advisor).

Table 7 Effects of Tele-urgent Care on Type of Case Resolution

Study | Outcome Description | Results
Telephone advice only
Cragg, 1996^22^ | Resolved during initial contact without referral | Deputized physician; 15 of 1082 (1.4%); Practice physician; 216 of 1,037 (20.8%)
Sen, 2019^28^ | Received advice of self-care | Physician; 594 (38.1%); Non-physician clinical advisor; 165 (15.7%); Percent difference; 22.4% (95% CI 19.0 to 25.7)
Outpatient care
Cragg, 1996^22^ | Referred to primary care services (ie, home visit, GP visit) | Deputized physician; 1,053 of 1,082 (97.3%); Practice physician; 817 of 1,037 (78.8%)
Sen, 2019^28^ | Referred by GP out of hours | Physician; 70 (4.5%); Non-physician clinical advisor; 441 (42.1%); Percent difference; 37.6% (95% CI 34.3 to 40.8)
Sen, 2019^28^ | Referred by GP in hours | Physician; 156 (10.0%); Non-physician clinical advisor; 7 (0.5%); Percent difference; 9.5% (95% CI 7.7% to 11.0%)
Sen, 2019^28^ | Referred to minor injuries unit/walk-in center | Physician; 225 (14.4%); Non-physician clinical advisor; 101 (9.6%); Percent difference; 4.8% (95% CI 2.2% to 7.4%)
Emergency services care
Cragg, 1996^22^ | Referred to emergency services | Deputized physician; 14 of 1,082 (1.3%); Practice physician; 4 of 1,037 (0.4%)
Sen, 2019^28^ | Referred to ED via ambulance | Physician; 112 (7.5%); Non-physician clinical advisor; 100 (9.5%); Percent difference; 2.0% (% (95% CI to 0.6 to 3.4)
Sen, 2019^28^ | Referred to ED via own transport | Physician; 284 (18.2%); Non-physician clinical advisor; 94 (9.0%); Percent difference; 9.2% (95% CI 6.6 to 11.9)

### Effects of Tele-urgent Care on Patient Safety

No eligible KQ 1 studies reported outcomes related to patient safety.

### Quality of Evidence for Key Question 1

ROB assessments for the KQ 1 included studies are summarized in Figures 3–6. The ROB for the single RCT was rated as some concerns due to bias in all factors except selective reporting of results (Figure 3).^22^ For the nonrandomized controlled designs, the 2 controlled before-and-after studies were both judged to have issues with potential confounding (Figure 4).^24,31^ Of those studies, 1 had an issue with selection of participants and serious concerns for missing data,^24^ and the other had additional risk of bias considerations related to outcome measurement and deviations for intended outcomes.^31^ For the 3 cohort studies, 1 was rated moderate ROB^21^ and 2 were rated serious ROB.^3,27^ The moderate ROB cohort study displayed concerns related to confounding and selection of participants.^21^ The other 2 serious ROB cohorts^3,27^ displayed the following concerns: serious confounding bias (n=2), serious concerns for selection of participants (n=1), serious concerns for missing data (n=1), measurement of outcomes (n=1).^27^

Of the cross-sectional studies, 4 were rated as good ROB^25,26,30,32^ and 3 as fair ROB^23,28,29^ (Figure 5). Patterns that led to judgments of more concerns for ROB included measurement and adjustment for key confounding variables (n=3), section of subjects from same population (n=1), and at least a 50% participation rate (n=1) (Figure 6).

Figure 3 Risk of Bias Assessment for the Included Cluster-randomized Trial

Figure 4 Risk of Bias Assessment for Nonrandomized Studies of Interventions

Figure 5 Risk of Bias Assessment for Cross-sectional Studies

Figure 6 Risk of Bias Assessment Across Included Coss-sectional Studies

## KEY QUESTION 2

A. Among adults, what are the adverse effects of tele-urgent care for low-acuity conditions (ie, inappropriate treatment, misdiagnosis, delayed diagnosis, patient deaths, provider burnout)?
B. Do the adverse effects of tele-urgent care for low-acuity conditions differ by (1) provider characteristics (ie, specialty, amount of telehealth experience, training) or (2) mode of delivery (ie, telephone, video, web, short message service)?

### Characteristics of Included Studies

Three studies were identified that addressed KQ 2.^36–38^ Study designs included 1 cluster RCT,^36^ 1 cohort,^37^ and 1 cross-sectional.^38^ The sample size of studies ranged from 298 to 1,167,468 with a median of 14,492 participants. The cluster RCT was rated as moderate ROB,^36^ the cohort was rated as fair,^37^ and the cross-sectional was rated as some concerns.^38^

### Key Points

- Few studies reported the adverse effects of interest. We found no studies that addressed delayed diagnosis or provider burnout. All included studies had ROB concerns.
- One moderate ROB retrospective cohort study found similar or better guideline-concordant antibiotic use for acute upper respiratory infections when treatment was delivered via tele-urgent care compared to in-person primary care or ED visits.
- One fair ROB cross-sectional study reported a small proportion of clinical safety complaints resulting from telephone-based after-hours care, many of which were not validated on objective review.

### Detailed Findings

We sought to describe the adverse effects of tele-urgent care for low-acuity conditions, defined as inappropriate treatment, misdiagnosis, delayed diagnosis, and provider burnout. We identified 3 studies that addressed these adverse effects.^36–38^ One study was a fair ROB cross-sectional study.^37^ Another was a moderate ROB retrospective cohort study.^38^ The last study was an RCT rated as having some concerns for ROB and used a comparator arm that mapped to our definition of tele-urgent care.^36^ Two studies were conducted in the United Kingdom^36,38^ and 1 in the United States.^37^ None of the relevant studies for this outcome reported analyses by a priori subgroups of interest (ie, provider characteristics, mode of delivery) to address KQ 2B. The types of adverse effects from tele-urgent care that were reported included receipt of inappropriate treatment and misdiagnosis (both objective and patient reported) and adverse clinical outcome (eg, deaths). We found no eligible studies that reported on delayed diagnosis or provider burnout as an adverse effect of tele-urgent care.

The first study was an RCT comparing a physician-led to a nurse-led telephone consultation intervention for out-of-hours care among primary care clinics in England.^36^ For the purposes of this outcome, only the physician-led condition met our definition of tele-urgent care. In this arm, a practice receptionist took patient details and passed them along to the doctor on call who then provided tele-urgent care. Adverse events of interest included death within 7 days. There were 67 deaths among the patient calls responded to by a general provider (n=7,308).

One retrospective cohort study reported on receipt of inappropriate treatment.^37^ Specifically, they compared the quality of antibiotic management in the context of acute respiratory infection between patients receiving care from tele-urgent care visits versus matched patients receiving care via in-person primary care or urgent care visits. Patients were matched based on age, sex, chronic conditions, location, insurance, and diagnostic category. They incorporated data from 39,974 tele-urgent visits, 1,084,056 primary care visits, and 212,837 urgent care visits. Of note, this study was limited to adults between 18 and 64 years of age who had pharmaceutical benefits. The study authors considered inappropriate treatment as a potential adverse effect of tele-urgent care; in the case of acute respiratory infection, this was defined as (1) guideline non-concordant antibiotic use, (2) unnecessary antibiotic use, or (3) no antibiotic use (when they may be indicated). Guideline non-concordant antibiotic use was lower among patients treated by tele-urgent compared with primary care (13% vs 15%, p <0.001) or urgent care (13% vs 14%, p < 0.001). Unnecessary antibiotic use was the same between tele-urgent and primary care (24% for each) and higher for urgent care (26%, p <0.001). No antibiotic use (when they may be indicated) was higher for tele-urgent than both primary care (17% vs 16%, p < 0.001) and urgent care (17% vs 14%, p < 0.001).

The last study reported on patient complaints of receipt of inappropriate treatment and misdiagnosis.^38^ Study authors conducted a retrospective cohort study (no comparison group) of patient contacts with an out-of-hours service provider in Ireland that included 445,598 telephone contacts. Out of these contacts, 234 patients registered 298 patient service complaints. One hundred twenty-six complaints (42%) were related to clinical care, of which 76 were clinical safety concerns (eg, dissatisfaction with physical exam) and 50 were quality-of-care concerns (eg, not receiving antibiotics as expected). Authors report that of the 45 complaints about diagnosis, 5 were confirmed as objective misdiagnoses, and 7 of 49 complaints about prescriptions were found to be prescription errors. Level of harm related to these complaints was classified as none/minimal in 102 (81%), minor in 19 (15%), moderate 4 (4%), major in 1 (1%), and catastrophic in 0 cases.

### Quality of Evidence for Key Question 2

All studies identified for KQ 2 had ROB concerns (Figure 7). The moderate ROB cluster RCT had concerns related to potential deviations from intended interventions.^36^ The cohort, rated as fair, had biases related to potential confounding and missing data.^37^ The cross-sectional was rated as some concerns and had issues related to sample size justification, measurement and dose of exposure, and measurement and adjustment for potential confounding variables.^38^

Figure 7 Risk of Bias Assessment Across Included KQ 2 Studies