# METHODS

We followed a standard protocol for this review. Each step was pilot tested to train and calibrate study investigators. The PROSPERO registration number is CRD42020191454. We adhered to the Preferred Reporting Items for Systematic Reviews and Meta Analyses (PRISMA) guidelines.^15^

## TOPIC DEVELOPMENT

This topic was proposed by a multidisciplinary governance structure led by the Office of Connected Care, which will become part of a larger department-level governance structure overseeing all contact center modernization, including administrative efforts. The results of this study will be relevant to the VHA.

## ANALYTIC FRAMEWORK

Prior to the start of our review, we developed an analytic framework (Figure 1) informed by existing research in tele-urgent care and the information needs of VHA operations partners. As depicted in the figure, we sought to explore the impact of tele-urgent care for low-acuity conditions on key clinical and health systems outcomes (KQ 1A) and adverse effects (KQ 2A) prioritized by VHA operations partners. As these effects may be influenced by other factors, we also sought to explore the moderating effects of provider characteristics (ie, specialty) and tele-urgent mode (eg, video vs telephone) (KQ 1B and KQ 2B).

Figure 1 Analytic Framework

## DATA SOURCES AND SEARCHES

We collaborated with an expert reference librarian to conduct a primary search from inception to February 13, 2020, of MEDLINE (via Ovid), Embase (via Elsevier), and CINAHL Complete (via EBSCO). We used a combination of MeSH keywords and selected free-text terms (eg, telehealth, urgent care) to search titles and abstracts (Appendix A). We hand searched previous systematic reviews conducted on this or a related topic for potential inclusion.

## STUDY SELECTION

Major inclusion criteria for this review were evaluations of tele-urgent care systems for initial care of low-acuity conditions initiated by patients or recommended by a primary care provider. To be considered “tele-urgent care,” the service must provide on-demand, unscheduled care for acute conditions with access to a prescribing provider not affiliated with the patient’s regular practice. To assist with screening of titles and abstracts, we incorporated the artificial intelligence technology, DistillerAI, developed as part of the DistillerSR software program (Evidence Partners Inc., Manotick, ON, Canada) as the second reviewer on 2,357 references. After most of the references were reviewed by at least 1 reviewer (n= 4,035), using prespecified inclusion/exclusion criteria (Table 1) at the title and abstract level, the DistillerAI program was trained on the database.

The DistillerAI program screened the remaining titles and abstracts and assigned a probability of relevance to the study questions. All citations with ≥ 50% probability of relevance were included to level 2 and underwent full-text review by 2 human reviewers. Articles included by an investigator or the AI algorithm underwent full-text screening. At the full-text screening stage, 2 independent investigators agreed on a final inclusion/exclusion decision. Disagreements between reviewers triggered a discussion between reviewers and involvement of a third reviewer to come to a consensus. Articles meeting eligibility criteria were included for data abstraction.

All results were tracked in both DistillerSR, a web-based data synthesis software program, and EndNote reference management software (Clarivate).

Table 1 Study Eligibility Criteria

Study Characteristic | Inclusion Criteria | Exclusion Criteria
Population | - KQ 1, KQ 2: Adults with low-acuity urgent conditions (≥18 years of age) and their families and caregivers; - KQ 2: Tele-urgent care providers (if included in harms) | - Inpatient populations; - Simulated patients; - Populations in residential facilities that provide regular medical care (eg, long-term care, nursing home); - Pediatric-only populations; - Mixed populations of adults and children if adults are ≤50% of the population and there is no subgroup analysis by age
Intervention | Tele-urgent care for low-acuity conditions, defined as care delivered remotely (eg, telephone, video conferencing) that includes medical services intended to provide on-demand initial treatment of an illness or injury that is considered urgent (but is not routine primary care nor emergency care) and that is initiated by a patient with a provider^a^ | - Interventions defined primarily as:; ○ Tele-monitoring; ○ Health coaching; ○ In-person presentations (eg, walk-ins to a patient’s existing primary care clinic); ○ Counseling; ○ Longitudinal care management (ie, more than 1 contact for an ongoing condition, routine follow-up); ○ Provider-to-provider communications or consultations beyond the initial transfer of information from a patient-initiated contact; ○ Urgent mental health crisis lines (eg, suicide hotlines); ○ Emergency medical services (eg, 911); ○ Same-day primary care provided by patient’s regular primary care provider/practice, including extended hours primary care; ○ Primary care delivered via an alternative modality (eg, tele-primary care); - Interventions related only to the use of remote triage for the following:; ○ Specific population or demographic (eg, pediatric-only, ethnic minority); ○ Specific condition (eg, depression) medical specialty (eg, orthopedics) or ongoing or chronic conditions (eg, diabetes); ○ Technical assessments not related to patient or health care outcomes; ○ General health education
Comparators | - KQ 1:; ○ Usual care/standard of care, waitlist control; ○ Other active comparator (eg, in-person care; - KQ 2: No comparator required | - KQ 1: No controls; - KQ 2: No exclusion criteria
Outco;esmes | - KQ 1: Patient, provider, system outcomes (eg, patient satisfaction, health care access, health care utilization, case resolution, cost, and patient safety); - KQ 2: Key adverse effects associated with telehealth (eg, inappropriate treatment, misdiagnosis, delayed diagnosis, patient deaths, provider burnout) | Any outcomes not listed
Timing | Any | Not applicable
Settings | - Outpatient general medical settings (eg, primary care, urgent care, emergency departments); - Community settings; - Direct-to-consumer commercial business; - Hospital-based urgent care | - Intervention delivered primarily in hospital inpatient setting; - Mass casualty event; - Specialty-specific settings for management of chronic medical conditions
Study design | - KQ 1: EPOC criteria studies^b^ that have prospective data collection:; ○ randomized trials; nonrandomized trials; controlled before-after studies; and interrupted time-series studies or repeated measures studies; ○ prospective and retrospective observational studies (ie, cohort studies, case control studies); ○ cross-sectional; - KQ 2: Same as for KQ 1 plus the following designs if they address adverse effects:; ○ Prospective and retrospective observational studies (ie, case-control, cohort); ○ Cross-sectional | - KQ 1, KQ 2:; ○ Descriptive studies with no outcomes data; ○ Qualitative studies; ○ Case reports and case studies; ○ Studies that included only outcomes data from one point in time (eg, post only, uncontrolled clinical study); ○ Modeling studies that used simulated data; - KQ 1: Not a clinical study (eg, editorial, nonsystematic review, letter to the editor); ○ Prospective and retrospective observational studies; ○ Clinical guidelines; ○ Measurement or validation studies; - May also exclude the following:; ○ Self-described pilot studies without adequate power to assess impact of intervention on outcomes; ○ Studies of small sample sizes (n <100)
Language | Any | Not applicable
Countries | OECD^c^ | Non-OECD
Publication types | Full publication in a peer-reviewed journal | Letters, editorials, reviews, dissertations, meeting abstracts, protocols without results

Abbreviations. EPOC=Effective Practice and Organisation of Care; OECD=Organization for Economic Cooperation and Development

a Relevant conditions include acute or subacute condition or exacerbation of a chronic condition (eg, mild asthma exacerbation) that does not constitute a true emergency, and is not for process of care (eg, request for a referral, order for routine lab testing, medication refill).

b See Cochrane EPOC criteria for definitions and details.^16^

c Organization for Economic Cooperation and Development (OECD) includes Australia, Austria, Belgium, Canada, Chile, Czech Republic, Denmark, Estonia, Finland, France, Germany, Greece, Hungary, Iceland, Ireland, Israel, Italy, Japan, Korea, Latvia, Luxembourg, Mexico, Netherlands, New Zealand, Norway, Poland, Portugal, Slovak Republic, Slovenia, Spain, Sweden, Switzerland, Turkey, United Kingdom, United States.

## DATA ABSTRACTION

Data from published reports were abstracted into a customized DistillerSR database by 1 reviewer and overread by a second reviewer. Disagreements were resolved by consensus or by obtaining a third reviewer’s opinion when consensus was not reached. Data elements include descriptors to assess applicability, quality elements, intervention details, and outcomes.

Key characteristics abstracted included patient descriptors (eg, age, sex, race), intervention characteristics (eg, provider type, tele-urgent service modality), comparator, and outcomes, as described previously. Multiple reports from a single study were treated as a single data point, prioritizing results based on the most complete and appropriately analyzed data. Although counted as 1 single study, we cited data from each paper separately. Key features relevant to applicability included the match between the sample and target populations (eg, age, Veteran status). For details of study characteristics, see Appendix B. Appendix C presents detailed intervention characteristics. Appendix D lists the excluded studies and reasons for exclusion.

## QUALITY ASSESSMENT

Quality assessment was done by the investigator abstracting or evaluating the included article; this initial assessment was overread by a second, highly experienced investigator. Disagreements were resolved by consensus between the investigators or, when needed, by arbitration by a third investigator. For randomized trials, we used the RoB 2 tool.^17^ For cross-sectional study designs, we used the NIH risk of bias tool.^18^ For non-randomized studies of interventions, we used the ROBINS- I.^19^ These criteria included adequacy of randomization and allocation concealment; comparability of groups at baseline; blinding; completeness of follow-up and differential loss to follow-up; whether incomplete data were addressed appropriately; validity of outcome measures; protection against contamination; selective outcomes reporting; and conflict of interest. We assigned a summary ROB score to individual studies.

## SYNTHESIS

We summarized the primary literature using relevant data abstracted from the eligible studies. Summary tables describe the key study characteristics of the primary studies: study design, patient demographics, and details of the intervention. We grouped outcomes into similar outcome types (eg, outpatient care utilization, emergency department utilization, hospitalization, total cost, index cost), intervention groups (eg, comparison by organizational structure of care, comparison by urgent care site) and study design (eg, randomized vs nonrandomized). We then determined the feasibility of completing a quantitative synthesis (ie, meta-analysis) to estimate summary effects. For meta-analyses, feasibility depends on the volume of relevant literature, conceptual homogeneity of the studies, and completeness of results reporting. We determined the heterogeneity of the included studies was too high to conduct meta-analysis.

Since quantitative synthesis was not feasible, we narratively analyzed the data. We gave more weight to the evidence from higher quality studies with more precise estimates of effect. The narrative synthesis focuses on documenting and identifying patterns in outcomes efficacy by intervention type across conditions and outcome categories. We analyzed potential reasons for inconsistency in treatment effects across studies by evaluating differences in the study population, intervention, comparator, and outcome definitions.

## RATING THE BODY OF EVIDENCE

The certainty of evidence for each KQ was assessed using the approach described by Grading of Recommendations Assessment, Development, and Evaluation (GRADE).^20^ We limited GRADE ratings to outcomes identified by the nominating VHA operations partners and Technical Expert Panel as critical to decision-making, which were identified through discussion. In brief, this approach required assessment of 4 domains: study design, risk of bias, consistency, directness, and precision. Additional domains used when appropriate were coherence, dose-response association, impact of plausible residual confounders, strength of association (magnitude of effect), and publication bias. These domains were considered qualitatively, and a summary rating of high, moderate, low, or very low certainty of evidence was assigned after discussion by 2 investigators.

## PEER REVIEW

A draft version of this report was reviewed by technical experts and clinical leadership. A transcript of their comments and our responses are in Appendix E.