# INTRODUCTION

Approximately 1 in 3 emergency department (ED) visits in the United States are non-emergent,^1^ potentially leading to unnecessary testing, treatment, and cost. Payers have long struggled to discourage non-emergent ED visits through patient education and higher copayments for ED visits.^1^ Delivery systems have built alternatives like same day or after-hours primary care, urgent care centers, and retail clinics.^1–3^ One strategy for delivering high quality, cost effective, and easily accessed urgent care is the use of telehealth modalities, or tele-urgent care.^3,4^ Tele-urgent care aims to provide unscheduled, on-demand initial treatment of an urgent illness or injury. Such conditions do not require emergency care but may not always be easy to address in a primary care setting.

The coronavirus pandemic affecting the United States in 2020 and beyond has made clear the importance of timely and accessible health care, especially for urgent health needs. Until recently, telehealth care has largely supplemented traditional office or urgent care visits. The COVID-19 pandemic, however, has transformed the health care landscape, as virtual care rapidly became the response to providing medical care while enforcing social distancing, improving health care access, and using resources efficiently.^5^ Today, telehealth modalities are a part of the natural experiment of the pandemic, where all health systems have been pushed to re-examine telehealth as a viable strategy that was once hindered by perceptions of cost, access, and quality constraints.^6,7^ Indeed, telehealth may create efficiencies in cost and time for health systems as well as access for patients in need of care.^8^ Early evidence from the pandemic demonstrated a growing acceptance by health care providers, patients, and health care organizations of virtual care for both routine and urgent care needs.^9–12^ Yet telehealth, and particularly virtual visits, are relatively new care options, and evidence related to quality and outcomes is limited. There are also concerns about the effectiveness of telehealth visits and impact on subsequent health care utilization as a result of unresolved symptoms.

The Veterans Health Administration (VHA) is the country’s largest integrated health system and, as such, has a mandate to care for Veterans across the entire United States and associated territories. Yet Veterans seeking care for urgent medical conditions may still experience barriers to accessing timely care due to the same challenges faced in civilian health care systems. Effective June 6, 2019, VHA began offering a new urgent care benefit that provides eligible Veterans with greater choice and access to care for the treatment of minor injuries and illnesses in their local communities. A growing subset of these visits have utilized virtual care. The VHA is also currently undergoing a modernization of their Clinical Contact Centers,^13^ which will ultimately be available to Veterans 24 hours a day, 7 days a week.^14^ Intended as an alternative to ED, urgent care centers, or primary care clinics for many low-acuity conditions, the VHA Clinical Contact Centers will include services like nurse advice, triage, and virtual visits with providers. Veterans Affairs (VA)-wide implementation of Clinical Contact Centers is planned for late 2022 and could have significant implications for Veterans facing temporal and geographic barriers to acute care. The VA Office of Connected Care requested this review to identify the current evidence base and the effect of tele-urgent care for low-acuity, nonemergent conditions on key outcomes such as health care utilization, patient satisfaction, cost, access, and safety. For this report, we define tele-urgent care as health care delivered remotely (eg, telephone, video conferencing) that includes medical services intended to provide on-demand initial treatment of an illness or injury that is considered urgent (but is not routine primary care nor emergency care) and that is initiated by a patient with a provider.

In collaboration with VHA operations partners, we developed the following key questions (KQs) for this review:

KQ 1 A. Among adults, what are the effects of tele-urgent care for low-acuity conditions on key clinical and health system outcomes (ie, utilization, patient satisfaction, cost, health care access, case resolution, patient safety)?
  B. Do the effects of tele-urgent care for low-acuity conditions differ by (1) provider characteristics (ie, specialty, amount of telehealth experience, training) or (2) mode of delivery (ie, telephone, video, web, short message service)?
KQ 2 A. Among adults, what are the adverse effects of tele-urgent care for low-acuity conditions (ie, inappropriate treatment, misdiagnosis, delayed diagnosis, patient deaths, provider burnout)?
  B. Do the adverse effects of tele-urgent care for low-acuity conditions differ by (1) provider characteristics (ie, specialty, amount of telehealth experience, training) or (2) mode of delivery (ie, telephone, video, web, short message service)?