# APPENDIX E PEER REVIEW DISPOSITION

Question Text | Reviewer Number | Comment | Response
Are the objectives, scope, and methods for this review clearly described? | 3 | Yes | Thank you
Are the objectives, scope, and methods for this review clearly described? | 5 | Yes | Thank you
Are the objectives, scope, and methods for this review clearly described? | 7 | Yes | Thank you
Are the objectives, scope, and methods for this review clearly described? | 8 | Yes | Thank you
Are the objectives, scope, and methods for this review clearly described? | 9 | Yes | Thank you
Is there any indication of bias in our synthesis of the evidence? | 3 | No | Thank you
Is there any indication of bias in our synthesis of the evidence? | 5 | No | Thank you
Is there any indication of bias in our synthesis of the evidence? | 7 | No | Thank you
Is there any indication of bias in our synthesis of the evidence? | 8 | No | Thank you
Is there any indication of bias in our synthesis of the evidence? | 9 | No | Thank you
Are you aware of any [underlined: published] or [underlined: unpublished] studies that we may have overlooked? | 3 | No | Thank you
Are you aware of any [underlined: published] or [underlined: unpublished] studies that we may have overlooked? | 5 | No | Thank you
Are you aware of any [underlined: published] or [underlined: unpublished] studies that we may have overlooked? | 7 | No | Thank you
Are you aware of any [underlined: published] or [underlined: unpublished] studies that we may have overlooked? | 8 | No | Thank you
Are you aware of any [underlined: published] or [underlined: unpublished] studies that we may have overlooked? | 9 | No | Thank you
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 3 | An impressive review and critique of current literature evaluating the impact of virtual care strategies. It is not surprising that many of the outstanding questions were either not directly addressed or did not yield consistent answers given the heterogeneity of the systems evaluated. One topic of special interest is comparing video vs. telephone for clinical effectiveness, patient satisfaction, etc. The lack of data on this subject is not surprising. I have gathered unpublished data suggesting that patient confidence in the provider is enhanced by video BUT the video appointments were targeted to conditions that most benefit from video (skin and eye concerns mostly). The same data set showed better clinical resolution with video for these problems. Data on Video vs. phone for more general clinical problems would be most interesting but the demographics of patients electing each modality can be quite different limiting the accuracy of any conclusions that might be drawn. VA has the opportunity to make a valuable contribution to the literature on this subject in the future. | Thank you
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 7 | The objectives, scope and methods are clearly described and appropriate reporting guidelines followed. Appropriate methods were used to reduce bias in the study selection process, e.g. piloting and selection by two independent reviewers. Excluded studies and reasons were included in an appendix. For extra transparency, you could have reported how disagreements between reviewers were resolved and a measure of agreement, e.g. kappa (unless I missed this). Synthesis of the included studies was guided by a pre-determined analytical framework and a publicly available protocol.; You searched three relevant databases and reference lists of related systematic reviews. The search strategies reported appear thorough and overall you should have good coverage of the published literature (although the search could have been strengthened by looking at sources such as the Cochrane Library). You don’t report any search for unpublished studies or grey literature so it’s certainly possible some could have been overlooked, though I don’t know of any specific examples.; In summary: I haven’t read the whole report in detail but it is methodologically strong and the conclusions follow from the evidence presented. The use of GRADE to assess certainty of evidence increases confidence in the findings, and applicability to the VHA system is explicitly considered | Thank you. We have augmented out Methods description to explicate how reviewer disagreement were resolved.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 8 | Well-conceived, systematically conducted review of important emerging topic area. | Thank you.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 9 | Thank you for the opportunity to review this evidence review on a very important and timely topic. I found this review to be informative, well-organized, and well-written. I think it will make a significant contribution and lay foundation for future work. I have a handful of minor comments for the authors to consider.; page 1, lines 26-27 paragraph 2 – the phrase “underutilization on non-physician providers” is somewhat vague. Do you mean underutilization of non-physician providers in primary care? I am wondering if your point is best made by saying there is a “shortage of primary care providers” as the composition of PCPs being physicians or non-physicians may be distracting and tangential, I think, to your main point. | We have edited this wording to improve clarity.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 9 | page 4 line 8- uses abbreviation COE which I don’t think was previously defined. | We have clarified with adding low certainty of evidence (COE).
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 9 | page 4 line 38 - there is a misplaced period after “health care” and I think there is a missing word. Also, I am not sure about the intended meaning of the phrase “deputizing physicians” and how that differs from “cooperative physicians.” | We have defined “deputizing” in the text. Deputized physicians differ from cooperative physicians as they are non-affiliated physicians who take the afterhours calls and cooperative physicians are those part of an established provider network.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 9 | I am also unsure about why satisfaction with provider communication is included with “health care access” rather than “patient satisfaction”. | We conceptualized “heath care access” as informed by the U.S. Office of Disease Prevention and Health Promotion’s Healthy People 2020 objectives. They defined health care access as the ability to provide health care when the need is recognized (ie, timeliness) and satisfaction with provider services and communication (ie, services).
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 9 | page 4 lines 49-53 - I am perplexed by the sentence “An additional study of calls to telephone-based urgent care services originally triaged to the ED by either a physician advisor or a non-physician clinical advisor produced more case resolution on the first contact than calls assessed by a non-clinical call handler”. I think the problem is the phrase “originally triaged to the ED” – so, the patient was seen in the ED, or diverted from the ED? (but if seen in the ED, then it was resolved there?) I think there is some information missing that is making this confusing. | This wording has been revised as “An additional study examined calls to a telephone-based urgent care where calls were triaged to the ED by the clinical support software. These same calls were then passed to an assessment service (prescribing provider: physician advisor or a non-physician clinical advisor) and produced more case resolution on the first contact than calls assessed initially by a non-clinical call handler then moved to a prescribing provider.” From the study description, patients that would have been advised to go to the ED by the clinical support software were passed to a clinical assessment service.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 9 | page 5 – line 12 – typo – I think “them” should be “that” | Revised to “that.”
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 9 | page 5 – line 14 – suggest changing “inappropriate care outcomes” to “inappropriate treatment outcomes” to stay consistent with language used elsewhere in the report | Changed to inappropriate “treatment” throughout
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 9 | page 12 – use of Distiller. I am confused by the numbers- your results show that you identified 4, 311 unique articles which you then applied inclusion and exclusion criteria. From the methods on page 12 it looks like you used 2765 articles to train Distiller, and then used Distiller to review 2,357 articles – which adds up to 5,122. And, you report that Distiller SR was a “second reviewer” – but wasn’t it the only reviewer for the “remaining titles and abstracts” that had <50% probability of relevance? | Thank you, we updated the language to clarify that the AI reviewed references as the second reviewer after it was trained on almost the full database reviewed by one person. The references that the AI included were reviewed by two people at the full-text review level.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 9 | page 22 – title “Effects on Outpatient Care Utilization” might be better titled “Effects on Subsequent Outpatient Care Utilization” – as the initial telehealth utilization is outpatient care. | This was revised to “Effects on Subsequent Outpatient Care Utilization.”
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 9 | Page 23- similarly, suggest section title be “Effects on Subsequent Emergency Department Utilization” | “Subsequent” was added.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 9 | page 23 – line 37 - extra work “in” and did you mean “NHS 111”? | Revised.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 9 | page 35 – As in executive summary, I am perplexed by the inclusion of patient satisfaction with communication in the section on access rather than in the patient satisfaction section. | We have revised this for clarity.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 9 | Figure 4B – needs better labels on the x axis – it took me a bit to realize that this represented % of studies. Figure 6 – also needs better label on the x axis | Thank you. These are standard figures for risk of bias in systematic reviews and the x axis is explained in the figure title.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 9 | page 42 – line 28 – “adverse effects prioritized by operations partners” – do you mean those listed in the i.e. part of KQ2A? Would specify as it is not immediately obvious | We have deleted this phrase from the results section for adverse events to improve clarity.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 9 | page 42 – line 51 “subgroups of interest” – is this the same thing as “adverse effects prioritized by operations partners”, or something else? | We have clarified that these are from the key questions of the review.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 9 | page 42 – line 52 – “adverse clinical outcome (i.., deaths)” – death is not listed in the i.e. for the question | Thank you. The key question includes this outcome of interest
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 9 | page 42 – lines 53-56 – you don’t comment on whether there were any studies showing adverse effects of delayed diagnosis. Also, how is the distinction between misdiagnosis v. delayed diagnosis being made (since delayed diagnosis usually starts with a misdiagnosis and a misdiagnosis is usually only detected when the true diagnosis is found, delayed from the initial presentation) | We agree these are aligned outcomes and that misdiagnosis can lead to delayed diagnosis. In general, we seek conceptualize outcomes as defined by study authors, when possible. We only identified one study that defined misdiagnosis. We did not find any studies that reported on delayed diagnosis and have clarified this this in the report results.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 9 | page 43- line 24 – need to define/describe what is meant by “direct-to-consumer care”, and specify if the comparison is being made to in-person primary care v. primary care via telehealth v. both | Thank you. We have revised this description to improve clarity and removed “direct-to-consumer” language.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 9 | page 43 - lines 32-43 – was there a comparison group for this study (if not, I suggest noting this) | There was no comparison group and we have now noted this in the text.