# APPENDIX D EXCLUDED STUDIES

| Exclusion Reason
Study | Not OECD | Population | Intervention | Comparator | Outcomes | Design
Adriaenssens, 2017^1^ | | X
Akhtar, 2018^2^ | | | X
Albert, 2015^3^ | | | | X
Allan, 2019^4^ | | | X
Allen-Davis, 1998^5^ | | | | | | X
Amarenco, 2007^6^ | | | X
Anderson, 2019^7^ | | | X
Anonymous, 1997^8^ | | | | X
Atiyeh, 2014^9^ | X
Balas, 1997^10^ | | | | | | X
Ball, 2008^11^ | | | X
Beard, 2017^12^ | | | X
Beech, 2000^13^ | | | X
Benger, 2004^14^ | | | X
Bhandari, 2014^15^ | | | X
Bjerring, 2012^16^ | | | X
Bladin, 2015^17^ | | X
Blank, 2012^18^ | | | | | | X
Bolli, 2005^19^ | | X
Brogan, 1998^20^ | | | | X
Brunett, 2015^21^ | | | | | X
Brunetti, 2013^22^ | | | | | | X
Brunner, 2018^23^ | | | X
Buja, 2015^24^ | | | | X
Bunn, 2005^25^ | | | | | | X
Bury, 2006^26^ | | X
Calitri, 2015^27^ | | | X
Campbell, 2013^28^ | | X
Campbell, 2015^29^ | | | X
Campbell, 2009^30^ | | | | X
Cherry, 2009^31^ | | | X
Chess, 2018^32^ | | X
Cheung, 2019^33^ | | X
Cook, 2015^34^ | | | X
Cook, 2010^35^ | | | X
Cooper, 2005^36^ | | | | X
Costa, 2018^37^ | X
Custer, 2003^38^ | | | X
Dahlgren, 2017^39^ | | | | X
Dale, 1998^40^ | | X
Dale, 1997^41^ | | | | X
Davis, 2019^42^ | | | | | X
Derkx, 2008^43^ | | X
Dhruva, 2007^44^ | | X
Donaghy, 2019^45^ | | | | | | X
Donley, 2017^46^ | | | X
Duke, 2012^47^ | | X
Dunt, 2005^48^ | | | | | | X
Dunt, 2006^49^ | | | | | | X
Dunt, 2007^50^ | | | | | | X
Eastwood, 2015^51^ | | | X
Eastwood, 2017^52^ | | | X
Ebert, 2019^53^ | | | X
Ekeland, 2018^54^ | | | | | | X
Elliott, 2015^55^ | | | | X
Eminovic, 2004^56^ | | | X
Evens, 1985^57^ | | X
Flynn, 1998^58^ | | | | X
Foster, 2019^59^ | | X
Foster, 2001^60^ | | | X
Gallagher, 1998^61^ | | | | | X
Giesen, 2006^62^ | | | X
Giesen, 2005^63^ | | | | | | X
Giesen, 2011^64^ | | | | | | X
Gillespie, 2016^65^ | | | X
Glynn, 2004^66^ | | | | X
Goodyear-Smith, 2005^67^ | | | X
Gould, 2009^68^ | | | X
Gray, 2012^69^ | | X
Greenhalgh, 2018^70^ | | | | | | X
Greenwald, 2019^71^ | | | | X
Grol, 2006^72^ | | | | | | X
Grove, 2019^73^ | | | X
Halter, 2007^74^ | | | | X
Handy, 2005^75^ | | | X
Hansen, 2011^76^ | | X
Hansen, 2011^77^ | | | | | | X
Hansen, 2008^78^ | | | | | X
Heidet, 2019^79^ | | | | | X
Heravian, 2018^80^ | | | | | | X
Hertzog, 2019^81^ | | | X
Holt, 2016^82^ | | | X
Howard, 2007^83^ | | | X
Howell, 2016^84^ | | | | | | X
Hsu, 2010^85^ | X
Huibers, 2012^86^ | | | | X
Huibers, 2013^87^ | | | X
Huibers, 2014^88^ | | | X
Huibers, 2011^89^ | | | X
Huilgol, 2019^90^ | | | X
Hulland, 1999^91^ | | X
Infinger, 2013^92^ | | | | X
Jansen, 2019^93^ | | | | | X
Jerant, 2005^94^ | | | | | | X
Jiwa, 2002^95^ | | | X
Jongeling, 2009^96^ | | | X
Kahn, 2016^97^ | | | | | | X
Keatinge, 2005^98^ | | X
Keizer, 2016^99^ | | | | | | X
Kelly, 2010^100^ | | | X
Killip, 2007^101^ | | | | | | X
Kinnersley, 2010^102^ | | | | | X
Klaassen, 2016^103^ | | X
Kleinknecht-Dolf, 2015^104^ | | X
Knight, 2010^105^ | | | | | | X
Krumperman, 2015^106^ | | | X
Kumar, 2006^107^ | | | X
Lambert, 2016^108^ | | X
Landrey, 2018^109^ | | | X
Langabeer, 2016^110^ | | | X
Langabeer, 2017^111^ | | | X
Lattimer, 2000^112^ | | | | | X
Lattimer, 2005^113^ | | | X
LaVela, 2013^114^ | | | X
Leask, 2019^115^ | | | X
Lee, 2019^116^ | | | X
Lee, 2003^117^ | | X
Lee, 2002^118^ | | X
Lessard, 2000^119^ | | X
Mann, 2002^120^ | | | | | | X
Manojlovich, 2015^121^ | | | | | | X
Martinez, 2018^122^ | | | X
Matar, 2015^123^ | | X
McAfee, 2020^124^ | X
McConnochie, 2006^125^ | | X
McDonnell, 2007^126^ | | | | X
McKinstry, 2002^127^ | | | X
McKinstry, 2002^128^ | X
McKinstry, 2009^129^ | | | | | | X
McLean, 2019^130^ | | | X
Mendenhall, 2018^131^ | | | X
Meng, 2015^132^ | | | X
Meyer, 2020^133^ | | | X
Miller, 2019^134^ | | | | | | X
Mira, 1995^135^ | | | X
Mohammed, 2012^136^ | | | | | X
Montalto, 1998^137^ | | X
Moreno, 1989^138^ | | | X
Morimura, 2011^139^ | | | | | | X
Mukamel, 2019^140^ | | X
Mulcahy, 2017^141^ | | | | X
Munro, 2000^142^ | | | X
Munroe, 1982^143^ | | | X
Murdoch, 2015^144^ | | | | | | X
Navratil-Strawn, 2014^145^ | | | X
Neimanis, 2009^146^ | | | X
Nord, 2019^147^ | | | | X
Noroxe, 2017^148^ | | | | | X
North, 2010^149^ | | | X
North, 2011^150^ | | | | | | X
O’Cathain, 2007^151^ | | | X
O’Cathain, 2014^152^ | | | | | X
Palen, 2012^153^ | | | X
Pallawala, 2001^154^ | X
Pathipati, 2016^155^ | | | X
Payne, 2001^156^ | | X
Perry, 1990^157^ | | | X
Philips, 2015^158^ | | | X
Player, 2018^159^ | | | | X
Pope, 2017^160^ | | | | | | X
Rahmqvist, 2011^161^ | | | | | | X
Rastogi, 2019^162^ | | | X
Ray, 2019^163^ | | X
Reitz, 2007^164^ | | | | | | X
Richards, 2004^165^ | | | X
Richards, 2004^166^ | | | | | | X
Richards, 2002^167^ | | | X
Richards, 2007^168^ | | | | X
Ricke, 1995^169^ | | X
Ritter, 2010^170^ | | | | X
Rogove, 2012^171^ | | | | | X
Roivainen, 2020^172^ | | | | | X
Rudin, 2019^173^ | | | X
Sabin, 1998^174^ | | | | | | X
Sandvik, 2010^175^ | | X
Schlachta, 2016^176^ | X
Schmid, 2017^177^ | | | X
Scott-Jones, 2008^178^ | | | | X
Shah, 2013^179^ | | | | | X
Simpson, 2000^180^ | | X
Smith, 2001^181^ | | | | X
Smits, 2019^182^ | | | X
Smits, 2016^183^ | | | X
Smits, 2018^184^ | | | | | X
Stoves, 2010^185^ | | | X
Stuart, 2000^186^ | | | X
Studnek, 2012^187^ | | | X
Thilsted, 2018^188^ | | | | | X
Turnbull, 2008^189^ | | | | X
Uscher-Pines, 2018^190^ | | | | | X
Uscher-Pines, 2015^191^ | X
Valero, 1999^192^ | | X
Van Donk, 2017^193^ | | | X
Van Uden, 2005^194^ | | | X
Varley, 2016^195^ | | | | | X
Verzantvoort, 2018^196^ | | | X
Walker, 2000^197^ | X
Wallace, 2008^198^ | | | X
Warren, 2015^199^ | | | X
Westall, 2015^200^ | X
Win, 2016^201^ | | | | | | X
Woods, 2013^202^ | | | X
Wootton, 2000^203^ | | | | X
Zinger, 2019^204^ | | | X

## REFERENCES IN APPENDIX D

1 Adriaenssens J, Hamelink A, Bogaert PV. Predictors of occupational stress and well-being in First-Line Nurse Managers: A cross-sectional survey study. International Journal of Nursing Studies. 2017;73:85–92.28551478
2 Akhtar M, Van Heukelom PG, Ahmed A, . Telemedicine Physical Examination Utilizing a Consumer Device Demonstrates Poor Concordance with In-Person Physical Examination in Emergency Department Patients with Sore Throat: A Prospective Blinded Study. Telemedicine Journal & E-Health. 2018;24(10):790–796.29470127
3 Albert SM, Agimi Y, Martich GD. Interest in mental health care among patients making eVisits. American Journal of Managed Care. 2015;21(12):867–872.26671698
4 Allan JL, Johnston DW, Powell DJH, . Clinical decisions and time since rest break: An analysis of decision fatigue in nurses. Health Psychology. 2019;38(4):318–324.30896218
5 Allen-Davis JT, Parker R, McGregor J, Beck A, McClatchey MW. Assessment of vulvovaginal complaints: agreement between phone and office management. Primary Care Update for Ob/Gyns. 1998;5(4):152.
6 Amarenco P, Nadjar M. Telemedicine for improving emergent management of acute cerebrovascular syndromes. International Journal of Stroke. 2007;2(1):47–50.18705988
7 Anderson E, Rãtsep M, Panov L, . Main causes of using primary care services and distribution of work between family doctor and family nurse in 2017. Eesti Arst. 2019;98(9):495–503.
8 Anonymous. Nurse telephone triage in out of hours primary care: a pilot study. South Wiltshire Out of Hours Project (SWOOP) Group. BMJ. 1997;314(7075):198–199.9022437
9 Atiyeh B, Dibo SA, Janom HH. Telemedicine and burns: an overview. Annals of Burns & Fire Disasters. 2014;27(2):87–93.26170782
10 Balas EA, Jaffrey F, Kuperman GJ, . Electronic communication with patients. Evaluation of distance medicine technology. JAMA. 1997;278(2):152–159.9214532
11 Ball GE. Out-of-hours emergency dental services in Scotland--a national model. British Dental Journal. 2008;205(9):485–487.18997701
12 Beard M, Orlando JF, Kumar S. Overcoming the tyranny of distance: An audit of process and outcomes from a pilot telehealth spinal assessment clinic. Journal of Telemedicine & Telecare. 2017;23(8):733–739.27534822
13 Beech B, Parry L, Valiani D. A pilot project to determine the demand for and utility of an out-of-hours psychiatric service run by on-call psychiatric nurses in an A&E department. Journal of Psychiatric & Mental Health Nursing (Wiley-Blackwell). 2000;7(6):547–553.
14 Benger JR, Noble SM, Coast J, Kendall JM. The safety and effectiveness of minor injuries telemedicine. Emerg Med J. 2004;21(4):438–445.15208226
15 Bhandari N, Shi Y, Jung K. Seeking health information online: does limited healthcare access matter? Journal of the American Medical Informatics Association. 2014;21(6):1113–1117.24948558
16 Bjerring OS, Fristrup C, Mortensen MB. Telephone hotline is an important part of overall patient management in upper gastrointestinal malignancies. Danish Medical Journal. 2012;59(8):A4487.22849981
17 Bladin CF, Moloczij N, Ermel S, . Victorian Stroke Telemedicine Project: implementation of a new model of translational stroke care for Australia. Internal Medicine Journal. 2015;45(9):951–956.26011155
18 Blank L, Coster J, O’Cathain A, . The appropriateness of, and compliance with, telephone triage decisions: a systematic review and narrative synthesis. Journal of Advanced Nursing (John Wiley & Sons, Inc.). 2012;68(12):2610–2621.
19 Bolli S, Melle GV, Laubscher B. After-hours paediatric telephone triage and advice: the Neuchatel experience. European Journal of Pediatrics. 2005;164(9):568–572.15906091
20 Brogan C, Pickard D, Gray A, Fairman S, Hill A. The use of out of hours health services: a cross sectional survey. BMJ. 1998;316(7130):524–527.9501716
21 Brunett PH, DiPiero A, Flores C, Choi D, Kum H, Girard DE. Use of a voice and video internet technology as an alternative to in-person urgent care clinic visits. Journal of Telemedicine & Telecare. 2015;21(4):219–226.25697491
22 Brunetti ND, De Gennaro L, Dellegrottaglie G, Procacci V, Di Biase M. Fast and furious: Telecardiology in acute myocardial infarction triage in the emergency room setting. European Research in Telemedicine. 2013;2(2):75–78.
23 Brunner J, Chuang E, Washington DL, . Patient-Rated Access to Needed Care: Patient-Centered Medical Home Principles Intertwined. Womens Health Issues. 2018;28(2):165–171.29339012
24 Buja A, Toffanin R, Rigon S, . Out-of-hours primary care services: demands and patient referral patterns in a Veneto region (Italy) Local Health Authority. Health Policy. 2015;119(4):437–446.25620776
25 Bunn F, Byrne G, Kendall S. The effects of telephone consultation and triage on healthcare use and patient satisfaction: a systematic review. British Journal of General Practice. 2005;55(521):956–961.
26 Bury G. General practice out-of-hours co-operatives - Population contact rates. Irish Medical Journal. 2006;99(3).
27 Calitri R, Warren FC, Wheeler B, . Distance from practice moderates the relationship between patient management involving nurse telephone triage consulting and patient satisfaction with care. Health & Place. 2015;34:92–96.25982703
28 Campbell JL, Britten N, Green C, . The effectiveness and cost-effectiveness of telephone triage of patients requesting same day consultations in general practice: study protocol for a cluster randomised controlled trial comparing nurse-led and GP-led management systems (ESTEEM). Trials [Electronic Resource]. 2013;14:4.
29 Campbell JL, Fletcher E, Britten N, . The clinical effectiveness and cost-effectiveness of telephone triage for managing same-day consultation requests in general practice: a cluster randomised controlled trial comparing general practitioner-led and nurse-led management systems with usual care (the ESTEEM trial). Health Technology Assessment (Winchester, England). 2015;19(13):1–212, vii–viii.
30 Campbell J, Roland M, Richards S, Dickens A, Greco M, Bower P. Users’ reports and evaluations of out-of-hours health care and the UK national quality requirements: a cross sectional study. British Journal of General Practice. 2009;59(558):e8–15.
31 Cherry A, Friel R, Dowden B, . Managing demand: telephone triage in acute maternity services. British Journal of Midwifery. 2009;17(8):496–500.
32 Chess D, Whitman JJ, Croll D, Stefanacci R. Impact of after-hours telemedicine on hospitalizations in a skilled nursing facility. American Journal of Managed Care. 2018;24(8):385–388.30130033
33 Cheung L, Leung TI, Ding VY, . Healthcare Service Utilization under a New Virtual Primary Care Delivery Model. Telemedicine Journal & E-Health. 2019;25(7):551–559.30192211
34 Cook EJ, Randhawa G, Guppy A, Large S. A study of urgent and emergency referrals from NHS Direct within England. BMJ Open. 2015;5(5).
35 Cook R, Thakore S, Morrison W, Meikle J. To ED or not to ED: NHS 24 referrals to the emergency department. Emergency Medicine Journal. 2010;27(3):213–215.20304891
36 Cooper D, Arnold E, Smith G, . The effect of deprivation, age and sex on NHS Direct call rates. British Journal of General Practice. 2005;55(513):287–291.
37 Costa G, Cabral O, Santana E, Lima G, Figueiredo I. Mobile emergency care service: A time-course assessment and characterization of demand. International Emergency Nursing. 2018;41:45–50.30458947
38 Custer M, O’Rourke KM, Roddy M, King R, Sprinkle L, Horne E. The impact of a nursing triage line on the use of emergency department services in a military hospital. Military Medicine. 2003;168(12):981–985.14719621
39 Dahlgren K, Holzmann MJ, Carlsson AC, Wandell P, Hasselstrom J, Ruge T. The use of a Swedish telephone medical advice service by the elderly - a population-based study. Scandinavian Journal of Primary Health Care. 2017;35(1):98–104.28277048
40 Dale J, Crouch R, Lloyd D. Primary care: nurse-led telephone triage and advice out-of-hours. Nursing Standard. 1998;12(47):41–45.
41 Dale J, Williams S, Crouch R, Patel A. A study of out-of-hours telephone advice from an A&E department. British Journal of Nursing. 1997;6(3):171–174.9104124
42 Davis CB, Marzec LN, Blea Z, . Antibiotic Prescribing Patterns for Sinusitis Within a Direct-to-Consumer Virtual Urgent Care. Telemedicine Journal & E-Health. 2019;25(6):519–522.30020851
43 Derkx HP, Rethans JJ, Muijtjens AM, . Quality of clinical aspects of call handling at Dutch out of hours centres: cross sectional national study. BMJ. 2008;337:a1264.18790814
44 Dhruva VN, Abdelhadi SI, Anis A, . ST-Segment Analysis Using Wireless Technology in Acute Myocardial Infarction (STAT-MI) Trial. Journal of the American College of Cardiology. 2007;50(6):509–513.17678733
45 Donaghy E, Atherton H, Hammersley V, . Acceptability, benefits, and challenges of video consulting: a qualitative study in primary care. British Journal of General Practice. 2019;69(686):e586–e594.
46 Donley E, McClaren A, Jones R, Katz P, Goh J. Evaluation and Implementation of a Telepsychiatry Trial in the Emergency Department of a Metropolitan Public Hospital. Journal of Technology in Human Services. 2017;35(4):292–313.
47 Duke M, Botti M, Hunter S. Effectiveness of pain management in hospital in the home programs. Clinical Journal of Pain. 2012;28(3):187–194.21904201
48 Dunt D, Day SE, Kelaher M, Montalto M. Impact of standalone and embedded telephone triage systems on after hours primary medical care service utilisation and mix in Australia. Australia & New Zealand Health Policy. 2005;2:30.16343354
49 Dunt D, Day SE, Kelaher M, Montalto M. The impact of standalone call centres and GP cooperatives on access to after hours GP care: a before and after study adjusted for secular trend. Family Practice. 2006;23(4):453–460.16702188
50 Dunt D, Wilson R, Day SE, Kelaher M, Gurrin L. Impact of telephone triage on emergency after hours GP Medicare usage: a time-series analysis. Australia & New Zealand Health Policy. 2007;4:21.17927836
51 Eastwood K, Morgans A, Smith K, Stoelwinder J. Secondary triage in prehospital emergency ambulance services: a systematic review. Emergency Medicine Journal. 2015;32(6):486–492.24788598
52 Eastwood K, Smith K, Morgans A, Stoelwinder J. Appropriateness of cases presenting in the emergency department following ambulance service secondary telephone triage: a retrospective cohort study. BMJ Open. 2017;7(10):e016845.
53 Ebert JF, Huibers L, Christensen B, Lippert FK, Christensen MB. Do callers to out-of-hours care misuse an option to jump the phone queue? Scandinavian Journal of Primary Health Care. 2019;37(2):207–217.31070507
54 Ekeland AG, Hansen AH, Bergmo TS. Clinical Videoconferencing as eHealth: A Critical-Realist Review and Qualitative Meta-Synthesis. Journal of Medical Internet Research. 2018;20(10):50–50.
55 Elliott AM, McAteer A, Heaney D, Ritchie LD, Hannaford PC. Examining the role of Scotland’s telephone advice service (NHS 24) for managing health in the community: analysis of routinely collected NHS 24 data. BMJ Open. 2015;5(8):e007293.
56 Eminovic N, Wyatt JC, Tarpey AM, Murray G, Ingrams GJ. First evaluation of the NHS direct online clinical enquiry service: a nurse-led web chat triage service for the public. Journal of Medical Internet Research. 2004;6(2):e17.15249266
57 Evens S, Curtis P, Talbot A, Baer C, Smart A. Characteristics and perceptions of after-hours callers. Family Practice. 1985;2(1):10–16.3988010
58 Flynn DM. Telephone triage as a strategy to ensure 24-hour access to medical care after the closure of supporting medical activity. Military Medicine. 1998;163(10):702–706.9795548
59 Foster CB, Martinez KA, Sabella C, Weaver GP, Rothberg MB. Patient Satisfaction and Antibiotic Prescribing for Respiratory Infections by Telemedicine. Pediatrics. 2019;144(3):09.
60 Foster J, Dale J, Jessopp L. A qualitative study of older people’s views of out-of-hours services. British Journal of General Practice. 2001;51(470):719–723.
61 Gallagher M, Huddart T, Henderson B. Telephone triage of acute illness by a practice nurse in general practice: outcomes of care. British Journal of General Practice. 1998;48(429):1141–1145.
62 Giesen P, Franssen E, Mokkink H, van den Bosch W, van Vugt A, Grol R. Patients either contacting a general practice cooperative or accident and emergency department out of hours: a comparison. Emergency Medicine Journal. 2006;23(9):731–734.16921097
63 Giesen P, Mokkink H, Ophey G, Drijver R, Grol R, Van Den Bosch W. How urgent is the presented morbidity at the out of hours primary care center? Huisarts en Wetenschap. 2005;48(5):207–210.
64 Giesen P, Smits M, Huibers L, Grol R, Wensing M. Quality of after-hours primary care in the Netherlands: a narrative review. Annals of Internal Medicine. 2011;155(2):108–113.21768584
65 Gillespie SM, Shah MN, Wasserman EB, . Reducing Emergency Department Utilization Through Engagement in Telemedicine by Senior Living Communities. Telemedicine journal and e-health : the official journal of the American Telemedicine Association. 2016;22(6):489–496.26741194
66 Glynn LG, Byrne M, Newell J, Murphy AW. The effect of health status on patients’ satisfaction with out-of-hours care provided by a family doctor co-operative. Family Practice. 2004;21(6):677–683.15528288
67 Goodyear-Smith F, Wearn A, Everts H, Huggard P, Halliwell J. Pandora’s electronic box: GPs reflect upon email communication with their patients. Informatics in Primary Care. 2005;13(3):195–202.
68 Gould ON, West S, Mancuso M. The perceived functions of alternative primary care options among adults in eastern Canada. Hospital Topics. 2009;87(4):1–7.19917545
69 Gray L, Dakin L, Counsell S, Edwards H, Wootton R, Martin-Khan M. ‘Online’ geriatric assessment procedure for older adults referred for geriatric assessment during an acute care episode for consideration of reliability of triage decisions. BMC Geriatrics. 2012;12:10.22433175
70 Greenhalgh T, Shaw S, Wherton J, . Real-World Implementation of Video Outpatient Consultations at Macro, Meso, and Micro Levels: Mixed-Method Study. Journal of Medical Internet Research. 2018;20(4):e150.29625956
71 Greenwald PW, Stern M, Clark S, . A Novel Emergency Department-Based Telemedicine Program: How Do Older Patients Fare? Telemedicine Journal & E-Health. 2019;25(10):966–972.30358524
72 Grol R, Giesen P, van Uden C. UpDate: international report. After-hours care in the United Kingdom, Denmark, and the Netherlands: new models: integrating telephone consultations, triaging, and physician visits or house calls offers a promising model for after-hours care. Health Affairs. 2006;25(6):1733–1737.17102200
73 Grove BE, Ivarsen P, de Thurah A, Schougaard LM, Kyte D, Hjollund NH. Remote follow-up using patient-reported outcome measures in patients with chronic kidney disease: the PROKID study - study protocol for a non-inferiority pragmatic randomised controlled trial. BMC Health Services Research. 2019;19(1):631.31484523
74 Halter M, Marlow T, Mohammed D, Ellison GTH. A patient survey of out-of-hours care provided by Emergency Care Practitioners. BMC Emergency Medicine. 2007;7.
75 Handy P, Pattman R. Triage up front. Sexually Transmitted Infections. 2005;81(1):59–62.15681725
76 Hansen EH, Hunskaar S. Understanding of and adherence to advice after telephone counselling by nurse: a survey among callers to a primary emergency out-of-hours service in Norway. Scandinavian Journal of Trauma, Resuscitation & Emergency Medicine. 2011;19:48.21892945
77 Hansen EH, Hunskaar S. Telephone triage by nurses in primary care out-of-hours services in Norway: an evaluation study based on written case scenarios. BMJ Quality & Safety. 2011;20(5):390–396.
78 Hansen EH, Hunskaar S. Development, implementation, and pilot study of a sentinel network (“The Watchtowers”) for monitoring emergency primary health care activity in Norway. BMC Health Services Research. 2008;8:62.18366754
79 Heidet M, Canoui-Poitrine F, Revaux F, . Factors affecting medical file documentation during telephone triage at an emergency call centre: a cross-sectional study of out-of-hours home visits by general practitioners in France. BMC Health Services Research. 2019;19(1):531.31362748
80 Heravian A, Chang BP. Mental health and telemedicine in the acute care setting: Applications of telepsychiatry in the ED. American Journal of Emergency Medicine. 2018;36(6):1118–1119.29103843
81 Hertzog R, Johnson J, Smith J, . Diagnostic Accuracy in Primary Care E-Visits: Evaluation of a Large Integrated Health Care Delivery System’s Experience. Mayo Clinic Proceedings. 2019;94(6):976–984.31171135
82 Holt TA, Fletcher E, Warren F, . Telephone triage systems in UK general practice: analysis of consultation duration during the index day in a pragmatic randomised controlled trial. British Journal of General Practice. 2016;66(644):e214–218.
83 Howard M, Goertzen J, Hutchison B, Kaczorowski J, Morris K. Patient satisfaction with care for urgent health problems: a survey of family practice patients. Annals of Family Medicine. 2007;5(5):419–424.17893383
84 Howell T. ED Utilization by Uninsured and Medicaid Patients after Availability of Telephone Triage. Journal of Emergency Nursing. 2016;42(2):120–124.26409919
85 Hsu MH, Chu TB, Yen JC, . Development and implementation of a national telehealth project for long-term care: a preliminary study. Computer Methods & Programs in Biomedicine. 2010;97(3):286–292.20092907
86 Huibers L, Keizer E, Giesen P, Grol R, Wensing M. Nurse telephone triage: good quality associated with appropriate decisions. Family Practice. 2012;29(5):547–552.22327415
87 Huibers L, Koetsenruijter J, Grol R, Giesen P, Wensing M. Follow-up after telephone consultations at out-of-hours primary care. Journal of the American Board of Family Medicine: JABFM. 2013;26(4):373–379.23833151
88 Huibers L, Moth G, Christensen MB, Vedsted P. Antibiotic prescribing patterns in out-of-hours primary care: a population-based descriptive study. Scandinavian Journal of Primary Health Care. 2014;32(4):200–207.25350313
89 Huibers L, Smits M, Renaud V, Giesen P, Wensing M. Safety of telephone triage in out-of-hours care: a systematic review. Scandinavian Journal of Primary Health Care. 2011;29(4):198–209.22126218
90 Huilgol YS, Miron-Shatz T, Joshi AU, Hollander JE. Hospital Telehealth Adoption Increased in 2014 and 2015 and Was Influenced by Population, Hospital, and Policy Characteristics. Telemedicine journal and e-health : the official journal of the American Telemedicine Association. 2019.
91 Hulland J, Avery AJ, Groom L, Boot D. Use of primary health care and accident and emergency (emergency department) services for children under 5 years outside normal office hours. Ambulatory Child Health. 1999;5(4):323–330.
92 Infinger A, Studnek JR, Hawkins E, Bagwell B, Swanson D. Implementation of prehospital dispatch protocols that triage low-acuity patients to advice-line nurses. Prehospital Emergency Care. 2013;17(4):481–485.23865776
93 Jansen T, Verheij RA, Schellevis FG, Kunst AE. Use of out-of-hours primary care in affluent and deprived neighbourhoods during reforms in long-term care: an observational study from 2013 to 2016. BMJ Open. 2019;9(3):e026426.
94 Jerant AF, Nesbitt TS. Heart failure disease management incorporating telemedicine: A critical review. Journal of Clinical Outcomes Management. 2005;12(4):207–217.
95 Jiwa M, Mathers N, Campbell M. The effect of GP telephone triage on numbers seeking same-day appointments. British Journal of General Practice. 2002;52(478):390–391.
96 Jongeling S, Chen MY, Bush MR, Bradshaw CS, Fairley CK. Risk profile of walk-in triage compared with an appointment-based phone-triage evening clinic. International Journal of STD & AIDS. 2009;20(2):135–137.19182063
97 Kahn EN, La Marca F, Mazzola CA. Neurosurgery and Telemedicine in the United States: Assessment of the Risks and Opportunities. World Neurosurgery. 2016;89:133–138.26852710
98 Keatinge D, Rawlings K. Outcomes of a nurse-led telephone triage service in Australia. International Journal of Nursing Practice (Wiley-Blackwell). 2005;11(1):5–12.
99 Keizer E, Maassen I, Smits M, Wensing M, Giesen P. Reducing the use of out-of-hours primary care services: A survey among Dutch general practitioners. European Journal of General Practice. 2016;22(3):189–195.27248713
100 Kelly M, Egbunike JN, Kinnersley P, . Delays in response and triage times reduce patient satisfaction and enablement after using out-of-hours services. Family Practice. 2010;27(6):652–663.20671002
101 Killip S, Ireson CL, Love MM, Fleming ST, Katirai W, Sandford K. Patient safety in after-hours telephone medicine. Fam Med. 2007;39(6):404–409.17549649
102 Kinnersley P, Egbunike JN, Kelly M, . The need to improve the interface between in-hours and out-of-hours GP care, and between out-of-hours care and self-care. Family Practice. 2010;27(6):664–672.20671001
103 Klaassen B, van Beijnum BJF, Hermens HJ. Usability in telemedicine systems-A literature survey. International Journal of Medical Informatics. 2016;93:57–69.27435948
104 Kleinknecht-Dolf M, Frei IA, Spichiger E, Muller M, Martin JS, Spirig R. Moral distress in nurses at an acute care hospital in Switzerland: results of a pilot study. Nursing Ethics. 2015;22(1):77–90.24917266
105 Knight K, Endacott R, Kenny A. Ambiguous and arbitrary: The role of telephone interactions in rural health service delivery. Australian Journal of Primary Health. 2010;16(2):126–131.21128573
106 Krumperman K, Weiss S, Fullerton L. Two Types of Prehospital Systems Interventions that Triage Low-Acuity Patients to Alternative Sites of Care. Southern Medical Journal. 2015;108(7):381–386.26192931
107 Kumar S, Yogesan K, Hudson B, Tay-Kearney ML, Constable IJ. Emergency eye care in rural Australia: Role of internet. Eye. 2006;20(12):1342–1344.16179932
108 Lambert D, Gale J, Hartley D, Croll Z, Hansen A. Understanding the Business Case for Telemental Health in Rural Communities. Journal of Behavioral Health Services & Research. 2016;43(3):366–379.26695645
109 Landrey AR, Harder VS, Sandoval MB, King JG, Ziegelman DS, MacLean CD. Utilization Outcomes of a Pilot Primary Care Team Redesign. Health Services Research & Managerial Epidemiology. 2018;5:2333392818789844.30202774
110 Langabeer JR, 2nd, Gonzalez M, Alqusairi D, . Telehealth-Enabled Emergency Medical Services Program Reduces Ambulance Transport to Urban Emergency Departments. The Western Journal of Emergency Medicine. 2016;17(6):713–720.27833678
111 Langabeer JR, Champagne-Langabeer T, Alqusairi D, . Cost-benefit analysis of telehealth in pre-hospital care. Journal of telemedicine and telecare. 2017;23(8):747–751.27913657
112 Lattimer V, Sassi F, George S, . Cost analysis of nurse telephone consultation in out of hours primary care: evidence from a randomised controlled trial. BMJ. 2000;320(7241):1053–1057.10764368
113 Lattimer V, Turnbull J, Burgess A, . Effect of introduction of integrated out of hours care in England: observational study. BMJ. 2005;331(7508):81–84.16002882
114 LaVela SL, Gering J, Schectman G, Locatelli SM, Weaver FM, Davies M. Improving the quality of telephone-delivered health care: a national quality improvement transformation initiative. Family Practice. 2013;30(5):533–540.23689516
115 Leask CF, Tennant H. Evaluation of an unscheduled care model delivered by advanced nurse practitioners in a primary-care setting. Journal of Research in Nursing. 2019;24(8):696–709.34394595
116 Lee HY, Kim JY, Na KY, . The role of telehealth counselling with mobile self-monitoring on blood pressure reduction among overseas Koreans with high blood pressure in Vietnam. Journal of Telemedicine & Telecare. 2019;25(4):241–248.29933721
117 Lee TJ, Baraff LJ, Guzy J, Johnson D, Woo H. Does telephone triage delay significant medical treatment?: Advice nurse service vs on-call pediatricians. Archives of Pediatrics & Adolescent Medicine. 2003;157(7):635–641.12860783
118 Lee TJ, Guzy J, Johnson D, Woo H, Baraff LJ. Caller satisfaction with after-hours telephone advice: nurse advice service versus on-call pediatricians. Pediatrics. 2002;110(5):865–872.12415022
119 Lessard JA, Knox R. Telehealth in a rural school-based health center. Journal of School Nursing. 2000;16(2):38–41.
120 Mann T, Colven R. A picture is worth more than a thousand words: enhancement of a pre-exam telephone consultation in dermatology with digital images. Academic Medicine. 2002;77(7):742–743.
121 Manojlovich M, Adler-Milstein J, Harrod M, . The Effect of Health Information Technology on Health Care Provider Communication: A Mixed-Method Protocol. JMIR Research Protocols. 2015;4(2):e72.26068442
122 Martinez KA, Rood M, Jhangiani N, Kou L, Boissy A, Rothberg MB. Association between Antibiotic Prescribing for Respiratory Tract Infections and Patient Satisfaction in Direct-to-Consumer Telemedicine. JAMA Internal Medicine. 2018;178(11):1558–1560.30285050
123 Matar R, Renapurkar R, Obuchowski N, Menon V, Piraino D, Schoenhagen P. Utility of hand-held devices in diagnosis and triage of cardiovascular emergencies. Observations during implementation of a PACS-based system in an acute aortic syndrome (AAS) network. Journal of cardiovascular computed tomography. 2015;9(6):524–533.26277273
124 McAfee JL, Vij A, Warren CB. Store-and-forward teledermatology improves care and reduces dermatology referrals from walk-in clinics: A retrospective descriptive study. Journal of the American Academy of Dermatology. 2020;82(2):499–501.31404572
125 McConnochie KM, Conners GP, Brayer AF, . Differences in Diagnosis and Treatment Using Telemedicine Versus In-Person Evaluation of Acute Illness. Ambulatory Pediatrics. 2006;6(4):187–195.16843248
126 McDonnell A, Esmonde L, Morgan R, . The provision of critical care outreach services in England: findings from a national survey. Journal of Critical Care. 2007;22(3):212–218.17869971
127 McKinstry B, Walker J, Campbell C, Heaney D, Wyke S. Telephone consultations to manage requests for same-day appointments: a randomised controlled trial in two practices. British Journal of General Practice. 2002;52(477):306–310.
128 McKinstry B, Walker J, Campbell C, Heaney D, Wyke S, Wallace P. Telephone consultations may be useful for people who request same-day appointments, but do not reduce workload. Evidence-Based Healthcare. 2002;6(4):154–155.
129 McKinstry B, Watson P, Pinnock H, Heaney D, Sheikh A. Telephone consulting in primary care: a triangulated qualitative study of patients and providers. British Journal of General Practice. 2009;59(563):e209–218.
130 McLean KA, Mountain KE, Shaw CA, . Can a smartphone-delivered tool facilitate the assessment of surgical site infection and result in earlier treatment? Tracking wound infection with smartphone technology (TWIST): protocol for a randomised controlled trial in emergency surgery patients. BMJ Open. 2019;9(10):e029620.
131 Mendenhall MA, Dyehouse K, Hayes J, . Practice transformation: Early impact of the oncology care model on hospital admissions. Journal of Oncology Practice. 2018;14(12):E739–E745.30265169
132 Meng D, Palen TE, Tsai J, McLeod M, Garrido T, Qian H. Association between secure patient-clinician email and clinical services utilisation in a US integrated health system: a retrospective cohort study. BMJ Open. 2015;5(11):e009557.
133 Meyer AND, Giardina TD, Spitzmueller C, Shahid U, Scott TMT, Singh H. Patient Perspectives on the Usefulness of an Artificial Intelligence-Assisted Symptom Checker: Cross-Sectional Survey Study. Journal of Medical Internet Research. 2020;22(1):e14679.32012052
134 Miller D, Loftus AM, O’Boyle PJ, . Impact of a telephone-first consultation system in general practice. Postgraduate Medical Journal. 2019;95(1129):590–595.31326942
135 Mira M, Cooper C, Maandag A. Contrasts between metropolitan and rural general practice in the delivery of after-hours care. Australian Family Physician. 1995;24(6):1064–1067.7625941
136 Mohammed MA, Clements G, Edwards E, Lester H. Factors which influence the length of an out-of-hours telephone consultation in primary care: a retrospective database study. BMC Health Services Research. 2012;12:430.23181707
137 Montalto M. How safe is hospital-in-the-home care? Medical Journal of Australia. 1998;168(6):277–280.9549535
138 Moreno CA. Utilization of medical services by single-parent and two-parent families. Journal of Family Practice. 1989;28(2):194–199.2915204
139 Morimura N, Aruga T, Sakamoto T, . The impact of an emergency telephone consultation service on the use of ambulances in Tokyo. Emergency Medicine Journal. 2011;28(1):64–70.20581386
140 Mukamel DB, Ladd H, Amin A, Sorkin DH. Patients’ preferences over care settings for minor illnesses and injuries. Health Services Research. 2019;54(4):827–838.31032907
141 Mulcahy D, O’Callaghan C, Hannigan A. Nurse Triage in an Irish Out-of-hours General Practice Co-Operative. Irish Medical Journal. 2017;110(3):530.28657243
142 Munro J, Nicholl J, O’Cathain A, Knowles E. Impact of NHS direct on demand for immediate care: observational study. BMJ. 2000;321(7254):150–153.10894694
143 Munroe D, Natale P. After-hours call in a primary care nursing practice. Nurse Practitioner. 1982;7(5):24–27.
144 Murdoch J, Varley A, Fletcher E, . Implementing telephone triage in general practice: a process evaluation of a cluster randomised controlled trial. BMC Family Practice. 2015;16:47.25887747
145 Navratil-Strawn JL, Ozminkowski RJ, Hartley SK. An economic analysis of a nurse-led telephone triage service. Journal of Telemedicine & Telecare. 2014;20(6):330–338.25059246
146 Neimanis I, Kaczorowski J, Howard M. After-hours services in capitation-funded primary care practice: use and satisfaction. Canadian Family Physician. 2009;55(10):1008–1009.e1001-1006.19826163
147 Nord G, Rising KL, Band RA, Carr BG, Hollander JE. On-demand synchronous audio video telemedicine visits are cost effective. American Journal of Emergency Medicine. 2019;37(5):890–894.30100333
148 Noroxe KB, Huibers L, Moth G, Vedsted P. Medical appropriateness of adult calls to Danish out-of-hours primary care: a questionnaire-based survey. BMC Family Practice. 2017;18(1):34.28292257
149 North F, Varkey P, Bartel GA, Cox DL, Jensen PL, Stroebel RJ. Can an office practice telephonic response meet the needs of a pandemic? Telemedicine Journal & E-Health. 2010;16(10):1012–1016.21058892
150 North F, Varkey P, Laing B, Cha SS, Tulledge-Scheitel S. Are e-health web users looking for different symptom information than callers to triage centers? Telemedicine Journal & E-Health. 2011;17(1):19–24.21214306
151 O’Cathain A, Knowles E, Munro J, Nicholl J. Exploring the effect of changes to service provision on the use of unscheduled care in England: population surveys. BMC Health Services Research. 2007;7:61.17466063
152 O’Cathain A, Knowles E, Turner J, Nicholl J. Acceptability of NHS 111 the telephone service for urgent health care: cross sectional postal survey of users’ views. Family Practice. 2014;31(2):193–200.24334420
153 Palen TE, Ross C, Powers JD, Xu S. Association of online patient access to clinicians and medical records with use of clinical services. JAMA. 2012;308(19):2012–2019.23168824
154 Pallawala PM, Lun KC. EMR based telegeriatric system. International Journal of Medical Informatics. 2001;61(2–3):229–234.11311676
155 Pathipati AS, Ko JM. Implementation and evaluation of Stanford Health Care direct-care teledermatology program. SAGE Open Medicine. 2016;4.
156 Payne F, Shipman C, Dale J. Patients’ experiences of receiving telephone advice from a GP co-operative. Family Practice. 2001;18(2):156–160.11264265
157 Perry JR, Caine N. General practitioners’ knowledge about patients and use of medical records in out of hours calls. British Journal of General Practice. 1990;40(334):190–193.
158 Philips H, Van Bergen J, Huibers L, . Agreement on urgency assessment between secretaries and general practitioners: an observational study in out-of-hours general practice service in Belgium. Acta Clinica Belgica. 2015;70(5):309–314.25819448
159 Player M, O’Bryan E, Sederstrom E, Pinckney J, Diaz V. Electronic Visits For Common Acute Conditions: Evaluation Of A Recently Established Program. Health Affairs. 2018;37(12):2024–2030.30633677
160 Pope C, Turnbull J, Jones J, Prichard J, Rowsell A, Halford S. Has the NHS 111 urgent care telephone service been a success? Case study and secondary data analysis in England. BMJ Open. 2017;7(5):e014815.
161 Rahmqvist M, Ernesater A, Holmstrom I. Triage and patient satisfaction among callers in Swedish computer-supported telephone advice nursing. Journal of Telemedicine & Telecare. 2011;17(7):397–402.21983224
162 Rastogi R, Martinez KA, Gupta N, Rood M, Rothberg MB. Management of Urinary Tract Infections in Direct to Consumer Telemedicine. Journal of General Internal Medicine. 2019;30:30.
163 Ray KN, Shi Z, Poon SJ, Uscher-Pines L, Mehrotra A. Use of Commercial Direct-to-Consumer Telemedicine by Children. Academic Pediatrics. 2019;19(6):665–669.30639759
164 Reitz GF, Stalenhoef P, Heg R, Beusmans G. Telephone triage in general practice. Huisarts en Wetenschap. 2007;50(13):656–659.
165 Richards DA, Godfrey L, Tawfik J, . NHS Direct versus general practice based triage for same day appointments in primary care: cluster randomised controlled trial. BMJ. 2004;329(7469):774.15377574
166 Richards DA, Meakins J, Godfrey L, Tawfik J, Dutton E. Survey of the impact of nurse telephone triage on general practitioner activity. British Journal of General Practice. 2004;54(500):207–210.
167 Richards DA, Meakins J, Tawfik J, . Nurse telephone triage for same day appointments in general practice: multiple interrupted time series trial of effect on workload and costs. BMJ. 2002;325(7374):1214.12446539
168 Richards SH, Pound P, Dickens A, Greco M, Campbell JL. Exploring users’ experiences of accessing out-of-hours primary medical care services. Quality & Safety in Health Care. 2007;16(6):469–477.18055893
169 Ricke J, Kleinholz L, Hosten N, . Telemedicine in rural areas. Experience with medical desktop-conferencing via satellite. Journal of Telemedicine & Telecare. 1995;1(4):224–228.9375147
170 Ritter LA, Robinette TR, Cofano J. Evaluation of a statewide telemedicine program. Californian Journal of Health Promotion. 2010;8(1):1–9.25750596
171 Rogove HJ, McArthur D, Demaerschalk BM, Vespa PM. Barriers to telemedicine: survey of current users in acute care units. Telemedicine Journal & E-Health. 2012;18(1):48–53.22082107
172 Roivainen P, Hoikka MJ, Raatiniemi L, Silfvast T, Ala-Kokko T, Kääriäinen M. Telephone triage performed by nurses reduces non-urgent ambulance missions: A prospective observational pilot study in Finland. Acta Anaesthesiologica Scandinavica. 2020.
173 Rudin RS, Fanta CH, Qureshi N, . A Clinically Integrated mHealth App and Practice Model for Collecting Patient-Reported Outcomes between Visits for Asthma Patients: Implementation and Feasibility. Applied clinical informatics. 2019;10(5):783–793.31618782
174 Sabin M. Telephone triage improves demand management effectiveness. hfm (Healthcare Financial Management). 1998;52(8):49–51.10182276
175 Sandvik H, Hunskar S. [Working style among regular general practitioners and other doctors in the out-of-hours services]. Tidsskrift for Den Norske Laegeforening. 2010;130(2):135–138.20125201
176 Schlachta C, Nguyen N, Ponsky T, Dunkin B, Schlachta CM, Nguyen NT. Project 6 Summit: SAGES telementoring initiative. Surgical Endoscopy. 2016;30(9):3665–3672.27270593
177 Schmid A, Hils S, Kramer-Zucker A, . Telemedically Supported Case Management of Living-Donor Renal Transplant Recipients to Optimize Routine Evidence-Based Aftercare: A Single-Center Randomized Controlled Trial. American Journal of Transplantation. 2017;17(6):1594–1605.27873477
178 Scott-Jones J, Lawrenson R, Maxwell N. Sharing after hours care in a rural New Zealand community--a service utilization survey. Rural & Remote Health. 2008;8(4):1024.18999904
179 Shah MN, Gillespie SM, Wood N, . High-intensity telemedicine-enhanced acute care for older adults: an innovative healthcare delivery model. Journal of the American Geriatrics Society. 2013;61(11):2000–2007.24164485
180 Simpson RG, Graham D, Martin K. Analysis of out of hours telephone consultation at the medical reception station Sennelager, British Forces Germany. Journal of the Royal Army Medical Corps. 2000;146(1):28–30.15241981
181 Smith S, Lynch J, O’Doherty K, Bury G. Patients’ views on out-of-hours care in general practice in Dublin. Irish Journal of Medical Science. 2001;170(3):192–194.12120974
182 Smits M, Colliers A, Jansen T, Remmen R, Bartholomeeusen S, Verheij R. Examining differences in out-of-hours primary care use in Belgium and the Netherlands: a cross-sectional study. European Journal of Public Health. 2019;29(6):1018–1024.31086964
183 Smits M, Hanssen S, Huibers L, Giesen P. Telephone triage in general practices: A written case scenario study in the Netherlands. Scandinavian Journal of Primary Health Care. 2016;34(1):28–36.26893132
184 Smits M, Keizer E, Giesen P, Deilkas ECT, Hofoss D, Bondevik GT. Patient safety culture in out-of-hours primary care services in the Netherlands: a cross-sectional survey. Scandinavian Journal of Primary Health Care. 2018;36(1):28–35.29334826
185 Stoves J, Connolly J, Cheung CK, . Electronic consultation as an alternative to hospital referral for patients with chronic kidney disease: a novel application for networked electronic health records to improve the accessibility and efficiency of healthcare. Quality & Safety in Health Care. 2010;19(5):e54–e54.
186 Stuart A, Rogers S, Modell M. Evaluation of a direct doctor-patient telephone advice line in general practice. British Journal of General Practice. 2000;50(453):305–306.
187 Studnek JR, Thestrup L, Blackwell T, Bagwell B. Utilization of prehospital dispatch protocols to identify low-acuity patients. Prehospital Emergency Care. 2012;16(2):204–209.22239124
188 Thilsted SL, Egerod I, Lippert FK, Gamst-Jensen H. Relation between illness representation and self-reported degree-of-worry in patients calling out-of-hours services: a mixed-methods study in Copenhagen, Denmark. BMJ Open. 2018;8(9):e020401.
189 Turnbull J, Martin D, Lattimer V, Pope C, Culliford D. Does distance matter? Geographical variation in GP out-of-hours service use: An observational study. British Journal of General Practice. 2008;58(552):471–477.
190 Uscher-Pines L, Fischer S, Tong I, Mehrotra A, Malsberger R, Ray K. Virtual First Responders: the Role of Direct-to-Consumer Telemedicine in Caring for People Impacted by Natural Disasters. Journal of General Internal Medicine. 2018;33(8):1242–1244.29691713
191 Uscher-Pines L, Mulcahy A, Cowling D, Hunter G, Burns R, Mehrotra A. Antibiotic prescribing for acute respiratory infections in direct-to-consumer telemedicine visits. JAMA Internal Medicine. 2015;175(7):1234–1235.
192 Valero MA, Arredondo MT, del Nogal F, Rodriguez JM, Torres D. Using cable television networks for interactive home telemedicine services. Journal of Telemedicine & Telecare. 1999;5 Suppl 1:S91–92.10534858
193 Van Donk P, Tanti ER, Porter JE. Triage and treat model of care: Effective management of minor injuries in the emergency department. Collegian. 2017;24(4):325–330.
194 Van Uden CJT, Ament AJHA, Hobma SO, Zwietering PJ, Crebolder HFJM. Patient satisfaction with out-of-hours primary care in the Netherlands. BMC Health Services Research. 2005;5.
195 Varley A, Warren FC, Richards SH, . The effect of nurses’ preparedness and nurse practitioner status on triage call management in primary care: A secondary analysis of cross-sectional data from the ESTEEM trial. International Journal of Nursing Studies. 2016;58:12–20.27087294
196 Verzantvoort NCM, Teunis T, Verheij TJM, van der Velden AW. Self-triage for acute primary care via a smartphone application: Practical, safe and efficient? PLoS ONE [Electronic Resource]. 2018;13(6):e0199284.
197 Walker J, Hill R, Green L. Tassie’s tele-rrific telehealth network: Linking primary health care services for better rural health outcomes. Australian Journal of Primary Health - Interchange. 2000;6(3–4):108–117.
198 Wallace DL, Jones SM, Milroy C, Pickford MA. Telemedicine for acute plastic surgical trauma and burns. Journal of Plastic, Reconstructive & Aesthetic Surgery: JPRAS. 2008;61(1):31–36.
199 Warren FC, Calitri R, Fletcher E, . Exploring demographic and lifestyle associations with patient experience following telephone triage by a primary care doctor or nurse: secondary analyses from a cluster randomised controlled trial. BMJ Quality & Safety. 2015;24(9):572–582.
200 Westall C, Spackman R, Nadarajah CV, Trepte N. Are hospital admissions reduced by Acute Medicine consultant telephone triage of medical referrals? Acute Medicine. 2015;14(1):10–13.25745644
201 Win AZ. Comparison of UK’s Minor Ailments Scheme and US’s retail clinic model: a narrative review. Primary Health Care Research & Development. 2016;17(6):622–627.26975702
202 Woods LW, Snow SW. The impact of telehealth monitoring on acute care hospitalization rates and emergency department visit rates for patients using home health skilled nursing care. Home Healthcare Nurse. 2013;31(1):39–45.23238623
203 Wootton R, McKelvey A, McNicholl B, . Transfer of telemedical support to Cornwall from a national telemedicine network during a solar eclipse. Journal of Telemedicine & Telecare. 2000;6 Suppl 1:S182–186.10794014
204 Zinger ND, Blomberg SN, Lippert F, Collatz Christensen H. Satisfaction of 30 402 callers to a medical helpline of the Emergency Medical Services Copenhagen: a retrospective cohort study. BMJ Open. 2019;9(10):e029801.