# REFERENCES

1 Institute of Medicine. Committee on Quality of Health Care in America. Crossing the Quality Chasm: A New Health System for the 21st Century. 2001.
2 Agency for Healthcare Research and Quality. Practice Faciliation Handbook. Training Modules for New Facilitators and Their Trainers. Available at: https://www.ahrq.gov/ncepcr/tools/pf-handbook/index.html. Accessed May 12, 2020.
3 Institute for Healthcare Improvement. Science of Improvement. Available at: http://www.ihi.org/about/Pages/ScienceofImprovement.aspx. Accessed July 14, 2020.
4 Improvement Science Research Network. What is Improvement Science? Available at: https://isrn.net/about/improvement_science.asp. Accessed July 14, 2020.
5 Shojania KG, Grimshaw JM. Evidence-based quality improvement: the state of the science. Health Aff (Millwood). 2005;24(1):138–50.15647225
6 Berta W, Cranley L, Dearing JW, . Why (we think) facilitation works: insights from organizational learning theory. Implement Sci. 2015;10:141.26443999
7 Liddy C, Laferriere D, Baskerville B, . An overview of practice facilitation programs in Canada: current perspectives and future directions. Healthc Policy. 2013;8(3):58–67.23968627
8 Kitson A, Harvey G, McCormack B. Enabling the implementation of evidence based practice: a conceptual framework. Qual Health Care. 1998;7(3):149–158.10185141
9 Department of Veterans Affairs. VHA National Transformational Coach Captain Program Informational Letter (addendum for Blueprint for Excellence). Veterans Health Administration. June, 2015.
10 Department of Veterans Affairs. VA National Center for Patient Safety. Available at: https://www.patientsafety.va.gov/features/VHA_s_HRO_journey_officially_begins.asp. Accessed July 24, 2020.
11 Baskerville NB, Liddy C, Hogg W. Systematic review and meta-analysis of practice facilitation within primary care settings. Ann Fam Med. 2012;10(1):63–74.22230833
12 Department of Veterans Affairs. Using Implementation Facilitation to Improve Care in the Veterans Health Administration. Available at: https://www.queri.research.va.gov/tools/implementation.cfm. Accessed July 14, 2020.
13 Bauer MS, Damschroder L, Hagedorn H, . An introduction to implementation science for the non-specialist. BMC Psychol. 2015;3(1):32–32.26376626
14 Cranley LA, Cummings GG, Profetto-McGrath J, . Facilitation roles and characteristics associated with research use by healthcare professionals: a scoping review. BMJ Open. 2017;7(8):e014384.
15 McKeever J, Rider N. Quality improvement coaching to build capacity within health departments: reflections and recommendations. J Public Health Manag Pract. 2014;20(1):52–6.24322687
16 Nagykaldi Z, Mold JW, Aspy CB. Practice facilitators: a review of the literature. Fam Med. 2005;37(8):581–8.16145629
17 Laferriere D, Liddy C, Nash K, . Navigating change: how outreach facilitators can help clinicians improve patient outcomes. J Am Board Fam Med. 2012;25(2):232–7.22403205
18 Goodwin MA, Zyzanski SJ, Zronek S, . A clinical trial of tailored office systems for preventive service delivery. The Study to Enhance Prevention by Understanding Practice (STEP-UP). Am J Prev Med. 2001;21(1):20–8.11418253
19 Due TD, Kousgaard MB, Waldorff FB, . Influences of peer facilitation in general practice - a qualitative study. BMC Fam Pract. 2018;19(1):75.29807529
20 Moher D, Liberati A, Tetzlaff J, . Preferred reporting items for systematic reviews and meta-analyses: the PRISMA statement. PLoS Med. 2009;6(7):e1000097–e1000097.19621072
21 Wolever RQ, Simmons LA, Sforzo GA, . A Systematic Review of the Literature on Health and Wellness Coaching: Defining a Key Behavioral intervention in Healthcare. Glob Adv Health Med. 2013;2(4):38–57.
22 Proctor E, Silmere H, Raghavan R, . Outcomes for implementation research: conceptual distinctions, measurement challenges, and research agenda. Adm Policy Ment Health. 2011;38(2):65–76.20957426
23 Cochrane Effective Practice and Organisation of Care (EPOC). Suggested risk of bias criteria for EPOC reviews. EPOC Resources for review authors, 2017. Available at: http://epoc.cochrane.org/resources/epoc-resources-review-authors. Accessed May 12, 2020.
24 Cumpston M, Li T, Page MJ, . Updated guidance for trusted systematic reviews: a new edition of the Cochrane Handbook for Systematic Reviews of Interventions. Cochrane Database Syst Rev. 2019;10:Ed000142.31643080
25 Cooke A, Smith D, Booth A. Beyond PICO: the SPIDER tool for qualitative evidence synthesis. Qual Health Res. 2012;22(10):1435–43.22829486
26 Critical Appraisal Skills Programme (CASP). Available at: https://casp-uk.net/. Accessed May 12, 2020.
27 Powell BJ, Waltz TJ, Chinman MJ, . A refined compilation of implementation strategies: results from the Expert Recommendations for Implementing Change (ERIC) project. Implement Sci. 2015;10:21.25889199
28 Michie S, van Stralen MM, West R. The behaviour change wheel: A new method for characterising and designing behaviour change interventions. Implement Sci. 2011;6(1):42.21513547
29 Consolidated Framework for Implementation Research. Strategy design [website]. Available at: https://cfirguide.org/choosing-strategies/. Accessed July 24, 2020.
30 Cochrane Training. Chaper 12: Synthesizing and presenting findings using other methods. Available at: https://training.cochrane.org/handbook/current/chapter-12#_Ref524788589. Accessed May 29, 2020.
31 Cooper HM. Research synthesis and meta-analysis : a step-by-step approach Los Angeles: Sage; 2010.
32 Booth A, Carroll C. How to build up the actionable knowledge base: the role of ‘best fit’ framework synthesis for studies of improvement in healthcare. BMJ Qual Saf. 2015;24(11):700–708.
33 Carroll C, Booth A, Leaviss J, . “Best fit” framework synthesis: refining the method. BMC Med Res Methodol. 2013;13(1):37.23497061
34 Damschroder LJ, Aron DC, Keith RE, . Fostering implementation of health services research findings into practice: a consolidated framework for advancing implementation science. Implement Sci. 2009;4:50.19664226
35 CFIR guide to constructs. Available at: https://cfirguide.org/constructs/. Accessed May 29, 2020.
36 Hultcrantz M, Rind D, Akl EA, . The GRADE Working Group clarifies the construct of certainty of evidence. J Clin Epidemiol. 2017;87:4–13.28529184
37 Lewin S, Booth A, Glenton C, . Applying GRADE-CERQual to qualitative evidence synthesis findings: introduction to the series. Implement Sci. 2018;13(Suppl 1):2.29384079
38 Dickinson WP, Dickinson LM, Jortberg BT, . A Cluster Randomized Trial Comparing Strategies for Translating Self-Management Support into Primary Care Practices. J Am Board Fam Med. 2019;32(3):341–352.31068398
39 Carroll JK, Pulver G, Dickinson LM, . Effect of 2 Clinical Decision Support Strategies on Chronic Kidney Disease Outcomes in Primary Care: A Cluster Randomized Trial. JAMA Network Open. 2018;1(6):e183377.30646261
40 Mold JW, Fox C, Wisniewski A, . Implementing asthma guidelines using practice facilitation and local learning collaboratives: a randomized controlled trial. Ann Fam Med. 2014;12(3):233–40.24821894
41 Meropol SB, Schiltz NK, Sattar A, . Practice-tailored facilitation to improve pediatric preventive care delivery: a randomized trial. Pediatrics. 2014;133(6):e1664–75.24799539
42 Dickinson WP, Dickinson LM, Nutting PA, . Practice facilitation to improve diabetes care in primary care: a report from the EPIC randomized clinical trial. Ann Fam Med. 2014;12(1):8–16.24445098
43 Parchman ML, Noel PH, Culler SD, . A randomized trial of practice facilitation to improve the delivery of chronic illness care in primary care: initial and sustained effects. Implement Sci. 2013;8:93.23965255
44 Chinman M, McCarthy S, Hannah G, . Using Getting To Outcomes to facilitate the use of an evidence-based practice in VA homeless programs: a cluster-randomized trial of an implementation support strategy. Implement Sci. 2017;12(1):34.28279207
45 Rask K, Kohler SA, Wells KJ, . Performance improvement interventions to improve delivery of screening services in diabetes care. J Clin Outcomes Manag. 2001;8(11):23–29.
46 Margolis PA, Lannon CM, Stuart JM, . Practice based education to improve delivery systems for prevention in primary care: randomised trial. BMJ. 2004;328(7436):388.14766718
47 Ornstein S, Jenkins RG, Nietert PJ, . A multimethod quality improvement intervention to improve preventive cardiovascular care: a cluster randomized trial. Ann Intern Med. 2004;141(7):523–32.15466769
48 van Bruggen R, Gorter KJ, Stolk RP, . Implementation of locally adapted guidelines on type 2 diabetes. Fam Pract. 2008;25(6):430–7.18718886
49 Due TD, Thorsen T, Kousgaard MB, . The effectiveness of a semi-tailored facilitator-based intervention to optimise chronic care management in general practice: a stepped-wedge randomised controlled trial. BMC Fam Pract. 2014;15:65.24716545
50 Engels Y, van den Hombergh P, Mokkink H, . The effects of a team-based continuous quality improvement intervention on the management of primary care: a randomised controlled trial. Br J Gen Pract. 2006;56(531):781–7.17007709
51 Lobo CM, Frijling BD, Hulscher ME, . Improving quality of organizing cardiovascular preventive care in general practice by outreach visitors: a randomized controlled trial Prev Med. 2002;35(5):422–9.12431890
52 Liddy C, Hogg W, Singh J, . A real-world stepped wedge cluster randomized trial of practice facilitation to improve cardiovascular care. Implement Sci. 2015;10:150.26510577
53 Hogg W, Lemelin J, Graham ID, . Improving prevention in primary care: evaluating the effectiveness of outreach facilitation. Fam Pract. 2008;25(1):40–8.18209107
54 Lemelin J, Hogg W, Baskerville N. Evidence to action: a tailored multifaceted approach to changing family physician practice patterns and improving preventive care. CMAJ. 2001;164(6):757–63.11276541
55 Harris MF, Parker SM, Litt J, . Implementing guidelines to routinely prevent chronic vascular disease in primary care: the Preventive Evidence into Practice cluster randomised controlled trial. BMJ Open. 2015;5(12):e009397.
56 Waltz TJ, Powell BJ, Matthieu MM, . Use of concept mapping to characterize relationships among implementation strategies and assess their feasibility and importance: results from the Expert Recommendations for Implementing Change (ERIC) study. Implement Sci. 2015;10:109.26249843
57 Perry CK, Damschroder LJ, Hemler JR, . Specifying and comparing implementation strategies across seven large implementation interventions: a practical application of theory. Implement Sci. 2019;14(1):32.30898133
58 Proctor EK, Powell BJ, McMillen JC. Implementation strategies: recommendations for specifying and reporting. Implement Sci. 2013;8:139.24289295
59 Liddy C, Singh J, Guo M, . Physician perspectives on a tailored multifaceted primary care practice facilitation intervention for improvement of cardiovascular care. Fam Pract. 2016;33(1):89–94.26644243
60 Liddy CE, Blazhko V, Dingwall M, . Primary care quality improvement from a practice facilitator’s perspective. BMC Fam Pract. 2014;15:23.24490746
61 Due TD, Thorsen T, Waldorff FB, . Role enactment of facilitation in primary care - a qualitative study. BMC Health Serv Res. 2017;17(1):593.28835276
62 Rogers ES, Cuthel AM, Berry CA, . Clinician Perspectives on the Benefits of Practice Facilitation for Small Primary Care Practices. Ann Fam Med. 2019;17(Suppl 1):S17–S23.31405872
63 McHugh M, Brown T, Liss DT, . Practice Facilitators’ and Leaders’ Perspectives on a Facilitated Quality Improvement Program. Ann Fam Med. 2018;16(Suppl 1):S65–S71.29632228
64 Hemler JR, Hall JD, Cholan RA, . Practice Facilitator Strategies for Addressing Electronic Health Record Data Challenges for Quality Improvement: EvidenceNOW. J Am Board Fam Med. 2018;31(3):398–409.29743223
65 Fernald D, Wearner R, Dickinson WP. Supporting primary care practices in building capacity to use health information data. EGEMS. 2014;2(3):1094.25848621
66 Buscaj E, Hall T, Montgomery L, . Practice Facilitation for PCMH Implementation in Residency Practices. Fam Med. 2016;48(10):795–800.27875602
67 Chase SM, Crabtree BF, Stewart EE, . Coaching strategies for enhancing practice transformation. Fam Pract. 2015;32(1):75–81.25281823
68 Godfrey MM, Andersson-Gare B, Nelson EC, . Coaching interprofessional health care improvement teams: the coachee, the coach and the leader perspectives. J Nurs Manag. 2014;22(4):452–64.23782339
69 Lessard S, Bareil C, Lalonde L, . External facilitators and interprofessional facilitation teams: a qualitative study of their roles in supporting practice change. Implement Sci. 2016;11:97.27424171
70 Kotecha J, Han H, Green M, . The role of the practice facilitators in Ontario primary healthcare quality improvement. BMC Fam Pract. 2015;16:93.26224104
71 Huston P, Hogg W, Martin C, . A process evaluation of an intervention to improve respiratory infection control practices in family physician offices. Can J Public Health. 2006;97(6):475–9.17203732
72 Mekki TE, Øye C, Kristensen B, . The inter-play between facilitation and context in the promoting action on research implementation in health services framework: A qualitative exploratory implementation study embedded in a cluster randomized controlled trial to reduce restraint in nursing homes. J Adv Nurs. 2017;73(11):2622–2632.28513876
73 Wang A, Pollack T, Kadziel LA, . Impact of Practice Facilitation in Primary Care on Chronic Disease Care Processes and Outcomes: a Systematic Review. J Gen Intern Med. 2018;33(11):1968–1977.30066117
74 Alagoz E, Chih MY, Hitchcock M, . The use of external change agents to promote quality improvement and organizational change in healthcare organizations: a systematic review. BMC Health Serv Res. 2018;18(1):42.29370791
75 Christianson MK, Sutcliffe KM, Miller MA, . Becoming a high reliability organization. Critical Care. 2011;15(6):314.22188677
76 Chassin MR, Loeb JM. The ongoing quality improvement journey: next stop, high reliability. Health Aff (Millwood). 2011;30(4):559–68.21471473
77 Agency for Healthcare Research and Quality. Patient Safety Network. High reliability. Available at: https://psnet.ahrq.gov/primer/high-reliability. Accessed July 24, 2020.
78 Gray CP, Yakir M, Hung DY. Physician Engagement With Metrics in Lean Primary Care Transformation. Qual Manag Health Care. 2018;27(3):117–122.29944622
79 Fischer MJ, Kourany WM, Sovern K, . Development, implementation and user experience of the Veterans Health Administration (VHA) dialysis dashboard. BMC Nephrol. 2020;21(1):136.32299383
80 MacLean CH, Kerr EA, Qaseem A. Time Out - Charting a Path for Improving Performance Measurement. N Engl J Med. 2018;378(19):1757–1761.29668361
81 Voils CI, Chang Y, Crandell J, . Informing the dosing of interventions in randomized trials. Contemp Clin Trials. 2012;33(6):1225–30.22841930
82 Robinson KA, Saldanha IJ, McKoy NA. Development of a framework to identify research gaps from systematic reviews. J Clin Epidemiol. 2011;64(12):1325–30.21937195
83 Stange KC, Goodwin MA, Zyzanski SJ, . Sustainability of a practice-individualized preventive service delivery intervention. Am J Prev Med. 2003;25(4):296–300.14580630
84 Deri Armstrong C, Taljaard M, Hogg W, . Practice facilitation for improving cardiovascular care: secondary evaluation of a stepped wedge cluster randomized controlled trial using population-based administrative data. Trials [Electronic Resource]. 2016;17(1):434.
85 Noel PH, Romero RL, Robertson M, . Key activities used by community based primary care practices to improve the quality of diabetes care in response to practice facilitation. Qual Prim Care. 2014;22(4):211–9.25685075