# ACKNOWLEDGMENTS

This topic was developed in response to a nomination by the Office of Veteran Access to Care, for the purpose of informing leadership, program offices, networks, and facilities on how to best measure the value of transformational coaching activities. The scope was further developed with input from the topic nominators (ie, Operational Partners), the ESP Coordinating Center, the review team, and the technical expert panel (TEP).

In designing the study questions and methodology at the outset of this report, the ESP consulted several technical and content experts. Broad expertise and perspectives were sought. Divergent and conflicting opinions are common and perceived as healthy scientific discourse that results in a thoughtful, relevant systematic review. Therefore, in the end, study questions, design, methodologic approaches, and/or conclusions do not necessarily represent the views of individual technical and content experts.

The authors gratefully acknowledge the following individuals for their contributions to this project:

## Operational Partners

Operational partners are system-level stakeholders who have requested the report to inform decision-making. They recommend technical expert panel (TEP) participants; assure VA relevance; help develop and approve final project scope and timeframe for completion; provide feedback on draft report; and provide consultation on strategies for dissemination of the report to field and relevant groups.

- Kathleen Glow-Morgan, LCSWR, VHA-CM
  National Transformational Coach Captain
  VISNs 19, 20 & 23 Certified Change Management Practitioner
  Office of Veteran Access to Care
- Christine Rovinski, MSN, APRN
  National Transformational Coach Captain
  Office of Veteran Access to Care

## Technical Expert Panel (TEP)

To ensure robust, scientifically relevant work, the TEP guides topic refinement; provides input on key questions and eligibility criteria, advising on substantive issues or possibly overlooked areas of research; assures VA relevance; and provides feedback on work in progress. TEP members are listed below:

- Carol Callaway-Lane, DNP, ACNP-BC
  Director, QI Workshop and Practicum-National Geriatric Scholars Program
  Associate Director, VA Quality Scholars Program, Nashville
  Assistant Professor, Vanderbilt University School of Nursing, Nashville
- Kay Calloway, MS, BSN, RN, CHPN, LeanBB, LSSBB, PMC, IA
  Associate Director, Systems Improvement & Consultation
  VHA10E2F Systems Redesign and Improvement
  VHA Office of Quality & Patient Safety (QPS)
- Laura Damschroder, MS, MPH
  Research Investigator
  VA Center for Clinical Management Research
  Ann Arbor, MI
- Michael Davies, MD, FACP
  Senior Medical Advisor to ADUSH Office of Veterans Access to Care (OVAC)
  Veterans Health Administration U.S. Department of Veterans Affairs
- Michael G. Goldstein, MD
  Associate Chief Consultant for Preventative Medicine
  VHA National Center for Health Promotion and Disease Prevention (10P4N)
  Patient Care Services (10P4)
- David Goodrich, EdD, MS, MA
  Implementation Scientist
  VA Center for Evaluation and Implementation Resources

## Peer Reviewers

The Coordinating Center sought input from external peer reviewers to review the draft report and provide feedback on the objectives, scope, methods used, perception of bias, and omitted evidence. Peer reviewers must disclose any relevant financial or non-financial conflicts of interest. Because of their unique clinical or content expertise, individuals with potential conflicts may be retained. The Coordinating Center and the ESP Center work to balance, manage, or mitigate any potential nonfinancial conflicts of interest identified.