# SUMMARY AND DISCUSSION

## SUMMARY OF EVIDENCE BY KEY QUESTION

### Key Question 1a

We mapped the outcome measures used across the 19 included trials to the practice, provider, and patient levels. The level with the most studies measuring at least 1 outcome was the provider level (15 studies), followed by patient (n=6), and then practice (n=5). Of the outcomes measures at the provider level, 6 studies used composite measures of multiple process of care behaviors.

### Key Question 1b

We identified 19 cluster-randomized trials (CRTs) that evaluated the effectiveness of transformational coaching for team-based health care improvement and practice change efforts on 4 process outcomes: adoption of targeted process of care activities, QI process goal attainment, team member knowledge, and team member self-efficacy. There were 6 low, 9 unclear, and 4 high risk of bias (ROB) trials. All but 1 of the 19 included trials were conducted within primary care settings. Coaches in these studies employed a median of 5.73 implementation strategies (range 3 to 9) to support teams around a specific QI project. The most common coaching strategy was to develop a formal implementation plan and the least common was developing stakeholder relationships. QI projects conducted by the coached teams typically targeted multiple simultaneous process of care activities requiring disparate clinical behaviors (eg, ordering a lab test, complicated patient counseling) but which were usually linked by a common goal (eg, improving management and outcomes for a specific disease). Overall, heterogeneity of outcome measure, timing of outcomes, and length of intervention prevented pooling of study outcomes in a meta-analysis.

The most commonly reported process of care outcome was adoption of targeted clinical care activities, which we divided into 7 subcategories based on the complexity of required activity: composite outcomes of multiple process of care activities, organizational process of care, appropriate documentation, appropriate medication prescriptions, patient counseling, exam or procedures, and appropriate ordering of test and vital signs. There is very low to low certainty of evidence that transformational coaching-like interventions are probably effective at improving composite processes of care, organizational processes of care, and ordering of lab tests and vital signs. It has uncertain effectiveness on improving appropriate documentation, provision of patient counseling, and conduct of appropriate exams and procedures and probably has no effect on prescription of diagnosis appropriate medications.

We found mixed results among 2 CRTs on the effect of transformational coaching on QI process goal attainment. No studies specifically assessed team member knowledge or self-efficacy after transformational coaching. One trial examined clinician self-confidence in assessment of various lifestyle behaviors as a secondary outcome after a coaching intervention compared to an unspecified control and found mixed results.

### Key Question 2

We found 16 studies that evaluated barriers and facilitators to implementation of a transformational coaching intervention. These 16 studies collected primary qualitative data from multiple perspectives including the coach delivering the intervention, the person or team receiving the intervention, and sometimes a combination. Multiple approaches were used for data collection including individual interviews, focus groups, surveys, and observational field notes. We examined themes related to barriers and facilitators of transformational coaching interventions across socioecologically informed CFIR domains of context (inner and outer setting), transformational coaching (intervention characteristics), individual or team receiving the coaching (characteristics of the individual), QI process or project (process), and the patient targeted by a given QI project.

Within the CFIR domains, we mapped 29 barriers and 24 facilitators across 15 CFIR constructs. Constructs with more facilitators than barriers—where there may be more opportunity to improve uptake—included culture (within context), adaptability (within intervention characteristics), and individual or team stages of change (within individual/team characteristics). Similarly, constructs with more barriers than facilitators and where problem-solving may need to be focused included design quality/packaging (QI project/process), knowledge and beliefs about intervention (team characteristics), and other personal attributes (team characteristics). We assessed the certainty of evidence for a selection of prioritized CFIR constructs. Specifically, we considered themes related to the following barriers to the uptake of coaching: high workload for coaches (moderate certainty of evidence); lack of engagement by practice team members (moderate certainty); evaluation (moderate certainty); unanticipated competing demands shift focus from QI activities (low certainty); lack of team knowledge about coaching and QI (low certainty); lack of team ability to work with data for project conduct (very low certainty); and when external policies were not aligned with the QI effort (very low certainty). We also considered facilitators, including active engagement by practices (moderate to high certainty of evidence), projects aligned with government guidelines (low certainty), and investing in training coaches (low certainty).

Overarching findings were:

- The person in the transformational coach-like role needs to see both the big picture and small details in order to overcome barriers and maximize facilitators.
- Care should be taken when introducing the coach and the project to properly set expectations for all involved.
- Working with teams to tailor coaching techniques and QI process activities to the teams needs and preferences is key for success.
- Coaches need to be well-versed and able to teach QI process skills to teams.
- Data acquisition and manipulation are critical for EHR-based QI activities and coaches who can support these QI activities for teams are well-positioned.
- Relationship building at all levels is critical (eg, between team members, teams and their stakeholders/leadership, and teams and coaches).

## PRIOR SYSTEMATIC REVIEWS

Our findings build on recently conducted reviews of roles similar to transformational coaching, specifically external change agents and practice facilitation. Baskerville and colleagues (2012) conducted a systematic review of 23 included articles looking at the impact of practice facilitation on evidence-based practice behavior.^11^ Baskerville’s approach differed from ours in that they considered adoption of evidence-based guidelines to be a common outcome measure and calculated standardized mean difference across studies and combined them for a pooled estimate. With this approach, they reported an effect size of 0.56 (95% CI 0.43 to 0.68) favoring practice facilitation in the adoption of evidence-based guidelines. Our findings are largely consistent with and build on those of Baskerville et al. Specifically, we considered adoption of evidence-based processes of care by complexity of the specific care activity or collection of care activities, and noted that there appears to be variation in the effect of coaching-type roles on different types of processes of care. A more recent review by Wang and colleagues (2018) examined the impact of practice facilitation on chronic disease management in primary care.^73^ They grouped outcomes by type of outcome (eg, lab vs diagnosis) within disease group (eg, cervical cancer process of care measures vs chronic kidney disease process of care). This approach is consistent with the way that interventions are often designed, specifically around management of a particular disease; however, it could mask differences in effect by the complexity of process of care. Across 25 studies, Wang et al concluded that process measures improved on average 8.8% with screening, and diagnosis improved the most, whereas we found the best evidence for a likely effect on composite process of care outcomes (which were sometimes disease-specific and sometimes more general such as preventive guidelines), organizational processes of care, counseling, and more simple tasks such as ordering of labs and vital signs. We found uncertain effect on documentation (including documentation of diagnoses) and likely no effect on prescription of disease appropriate medications.

Prior reviews have also looked at which aspects of coach-like roles are likely contributors to an overall effect. Alagoz and colleagues (2018) explored the role of external change agents in promoting changes health care organization in small primary care clinics across 21 included studies.^74^ They concluded that clinic-level, regular, individualized follow-up via practice facilitation models are the most effective approaches, while the most commonly employed are academic detailing and audit and feedback. Similarly, we found that audit and feedback (89% studies) and academic detailing, or educational outreach visits (68% studies), were among the most commonly used implementation strategies along with developing a formal implementation plan (95%) and distributing educational materials (74%), and that only 10 of 19 studies employed ongoing consultation (53%). Baskerville et al found that tailoring, intervention intensity (average number of contacts x average meeting time in hours), and number of intervention practices per facilitator modified the effect of practice facilitation.^11^ Similar to Baskerville et al, we found that coaches need to be flexible to be effective and need to be able to adjust by team to meet the needs of individual practices (ie, tailoring); however, this could mean less time for some teams and more for others. In addition to considerations of intervention length and intensity, we found that certain implementation strategies used by transformational coaches were seen as more helpful than others (ie, technical data support, instruction of specific QI strategies, and stakeholder and leadership engagement). To date, however, these strategies have been uncommon in coaching-like interventions (only 37%, 37%, and 10% respectively).

## CLINICAL POLICY IMPLICATIONS

The findings from our review are generalizable broadly to coach-led support for team-based QI activities, including those conducted within the VA. The VA has a longstanding and ongoing commitment to providing high-quality patient-centered care, and continues to seek effective strategies that can accelerate the speed and impact of improvement efforts. The results from this review suggestion that transformational coaching could play an important role in the VA’s overall commitment to QI. For example, we found that coaches can play a critical role in facilitating access to and use of data and technical resources for QI activities. Currently, the VA is planning a national transition in electronic health record of use from the VA-created Computerized Patient Record System (CPRS) to a new system developed by Cerner. One impact of the coming medical record transition will be a significant learning curve for QI teams related to gathering of EHR data to measure and evaluate the success of their improvement projects. Transformational coaching could support teams during this technological transition. Another example is that we found that interventions like transformational coaching probably have benefit on ordering of labs and vital signs but not prescription of diagnosis appropriate medications, and that teams with greater levels of process engagement have greater uptake of transformational coaching. These findings could contribute to organizational decisions about which QI projects and which clinical teams could most benefit from transformational coaching support. One current VA effort that is already making use of transformational coaching is the national effort to become a high-reliability organization (HRO). Health care systems that are HROs employ processes and practices to effectively target and resolve emerging safety problems to promote high-quality care.^75^ Becoming an HRO requires process improvement in the pursuit of prioritizing safety as a critical component of organizational conduct.^76,77^

Our findings from mapping the outcomes measured in effectiveness evaluations of coach-like interventions could also inform ongoing efforts to improve the quality of VA care. Specifically, the choice of metrics with which to determine the success of QI and coaching activities need to be carefully considered. We found a variety of outcomes used to assess the effectiveness of the coach-like role, including both practice- and provider-level process outcomes as well as patient-level outcomes. An appropriate metric for a given situation must be clinically meaningful and significant to parties at each of these levels (ie, administrative leadership and providers).^78^ Examples of stakeholder-driven, purposeful selection of quality metrics for VA QI efforts demonstrate the rigor required for the selection process.^79^ Recent work by the American College of Physicians has outlined criteria with which to assess the validity of quality measures,^80^ including domains such as importance, appropriate care, clinical evidence base, measure specifications, and measure feasibility and applicability. Future work in this area could explore application of these criteria to common outcomes used to assess coaching-like interventions to improve the relevance and utility of studied metrics.

## LIMITATIONS

Our findings should be considered within the context of the limitations of the identified literature and of our approach.

### Limitations of Identified Literature

#### Publication Bias

Our findings showed a mix of both positive and negative findings which argues against a significant publication bias, however, given that interventions like transformational coaching are often employed in the context of QI, many of them may never be published. Even when published, not all relevant data may be included. In particular, some studies were excluded for not including eligible process of care outcomes.

#### Study Quality

We noted some common issues specific to study quality. First, all of the included studies for KQ 1b were cluster-randomized controlled trials (CRTs), including stepped-wedge studies, which is appropriate for a team/practice level intervention such as transformational coaching. However, recruiting and randomizing in clusters creates some particular methodologic challenges. For example, some studies experienced uneven dropout of entire practices across study arms, leading to clinically significant unevenness across arms. In addition, CRTs did not always provide adequate description of both patient- and practice-level characteristics from which to judge the degree of similarity across study arms. Also important for CRTs is incorporation of the effect of clusters for any patient-level analysis (ie, intraclass correlation and other approaches); however, this was not always done or at least not always described. Lack of consideration of clustering with patient-level data could over or under estimate true effects. Finally, many included studies did not clearly state the intended primary outcome, or included a large number of apparent primary outcomes (sometimes over 20) without clear power calculations supporting their approach.

For KQ 2 studies, common quality concerns related to the lack of clarity around the relationship of individuals collecting primary qualitative data to the participants, and poorly described recruitment procedures.

#### Heterogeneity

There were multiple sources of heterogeneity across the included studies. First and foremost, the specific activities of the transformational coach-like roles were varied and not always clearly described. In order to make adequate comparisons and to inform implementation, clear descriptions of not only the coaching activities but also the components of intervention dose (specifically duration, frequency, and amount^81^) will be critical. Moreover, using a framework for strategies employed by the transformational coach (such as CFIR used in this report) will support such comparisons and applications. The duration and time intensity also varied across included studies and could be considered as potential effect modifier in the future. Other contributors to heterogeneity include the size and location of the practices (eg, rural vs urban, small vs large), the background training of the coaches themselves (eg, nonclinical professionals vs nurses vs physicians), the targeted clinical process of care for QI (eg, general QI capacity, disease specific, or general preventive care), and the way outcomes were defined and collection (eg, mean proportions, discrete scales, or as a continuous variable). Diverse stakeholder involvement is inconsistently used in both clinical research and QI projects. Incorporating opinions from providers and patients in addition to clinical and administrative leadership could ensure that outcome measures are valid and relevant to all involved parties. In particular for KQ 2 included studies, there was a diversity among who collected the qualitative data. While this can advantageous and contribute to the richness of study findings, if not properly justified or balanced by other perspectives, it can present biased results.

### Limitations of Review Approach

It is important to consider methodologic decisions made in our approach to this review and how they may have impacted our findings. First, our review was guided by the operational definition of transformational coaching, which is a role defined within the VA setting and which is similar but not identical to other roles (eg, practice facilitator, outreach visitor) intended to support the implementation of evidence-based practices within clinical care settings. While introducing heterogeneity into the included studies, drawing from across scholarly fields offered depth and breadth to the literature included in this review. The eligibility limitations imposed by this operational definition of transformational coaching may have led to the exclusion of related literature that could be relevant to this topic. Second, we limited studies in KQ 1 to those that provided high-quality evidence for coaching effectiveness as determined by EPOC criteria. While supporting the validity of our findings, we have likely missed some QI interventions that did not meet these stringent criteria. Third, we only included studies that supported an isolation of treatment effect for a coaching-like intervention. This led to the inclusion of studies with a minor component of such commonly co-delivered interventions as learning collaboratives but exclusion of studies in which a co-delivered intervention was a major component (defined as using a longitudinal approach). As coaching-like strategies are often employed in conjunction with other interventions, this may have excluded studies that could provide valuable information. Fourth, after extensive consideration and exploration, we determined that the process of care measures used across included studies for KQ 1 were too heterogeneous with respect to the measured outcome and the type of outcome data provided (eg, proportions vs means, discrete scales vs dichotomized variables) such that conversion to a common summary statistic for a pooled analysis was statistically inappropriate. This choice limited our ability to draw conclusions about effect size; however, we employed guidance from established review organizations to conduct a systematic vote-counting method to conduct our meta-synthesis.^30^ Fifth, for KQ 2, we selected the CFIR framework to guide our analysis of included studies about the barriers and facilitators to uptake of transformational coaching. As there are multiple other potentially relevant frameworks that could have been chosen for the best-fit framework approach, it is possible that other framework choices could have led to different conclusions. Moreover, our approach to synthesis in KQ 2 allowed for overlap in the CFIR domains, particularly for the coach. Coaches have the ability to intervene at both the team level and improvement strategy level to drive the process toward the desired goal. The inclusion of both organizational and coach-implemented facilitators may appear to conflate the facilitator’s results; however, they are intrinsically intertwined. Finally, we conducted a certainty of evidence assessment only for those KQ 2 findings mapped to CFIR constructs prioritized by our operational partners. It is possible that other constructs would be prioritized in different contexts.

### Applicability of Findings to the VA Population

One VA-based study^44^ met our eligibility criteria and was included in the analysis for KQ 1b. However, we believe that all of the included studies provide reasonably direct evidence that would be applicable to the VA primary care setting. Many were conducted in national health care systems outside the United States (ie, Denmark, Canada), which share characteristics of common infrastructure and parallel processes. Studies that included small private primary care practices provide less direct evidence, though still could inform the use of transformational coaching-like interventions in small VA community based outpatient clinics. As almost all included studies were conducted in the primary care setting, these findings may not be applicable to specialty care.

## RESEARCH GAPS/FUTURE RESEARCH

We identified several gaps in the existing literature that warrant further consideration. To systematically identify the existence of, and reason for, these gaps, we used an existing framework (Tables 20 and 21). Robinson and colleagues^82^ propose the identification of gaps categorically using the PICOTS framework (population, intervention, comparator, outcome, timing, and setting) and classification by reason (insufficient or imprecise information, biased information, inconsistency and/or not the right information). We have adapted this framework approach to identify gaps in the qualitative literature examined in KQ 2 using the SPIDER framework.^25^

Table 20 Evidence Gaps Related to Effectiveness of Transformational Coaching on Process of Care Outcomes

Evidence Gap | Reason | Types of Studies to Consider
Population
- Clinical teams smaller than the practice level (eg, Patient Aligned Care Teams) | - Insufficient information | - CRTs including stepped-wedge trials
Interventions
- CRTs including stepped-wedge trials; - Coaching interventions employing implementation strategies identified as most important and likely most effective (eg, technical assistance); - Coaching interventions with transparent description of implementation strategies both planned and delivered; - Multiple types of coaching interventions, including those designed to promote general QI capacity, those promoting predetermined QI projects, and those promoting team-driven QI projects | - CRTs including stepped-wedge trials; - Insufficient information | - CRTs including stepped-wedge trials
Comparators
- Continued comparison to usual care/enhanced usual care | - Insufficient information | - CRTs including stepped-wedge trials
Outcomes
- Consistent use of common clinical process of care measures comparing end of intervention to baseline by treatment arm | - Biased information | - CRTs including stepped-wedge trials
Setting
- Clinical contexts outside of primary care | - Insufficient information | - CRTs including stepped-wedge trials

Abbreviations: CRT=cluster-randomized trial; QI=quality improvement

Table 21 Evidence Gaps Related to Barriers and Facilitators of Transformational Coaching Implementation

Evidence Gap | Reason | Types of Studies to Consider
Sample
- All team members receiving coaching (/e, not restricting samples to just physicians or facilitators); - Leaders and stakeholders peripherally involved with team receiving coaching with relationship to team clearly delineated; - Patient population which is the focus of a given team’s QI project | - Insufficient information | - Individual interviews balanced by training/team role; - Focus groups separated by training/team role; - Surveys
Phenomenon of interest
- Coaching interventions without non-coaching components; - Multiple types of coaching interventions, including those designed to promote general QI capacity, those promoting predetermined QI projects, and those promoting team-driven QI projects; - Coaches’ decision making with regard to coaching strategy selection; - Organizational factors that facilitate/hinder the implementation of coaching interventions; - How, for whom, and when coaching works during the QI process | - Insufficient information | - Individual interviews separated by training/team role and throughout the coaching/QI; - Focus groups separated by training/team role surveys; - Mixed/multiple method; - Observation
Design
- Continue inclusion of primary data collection from individuals involved in transformational coaching-like interventions | - Insufficient information | - Mixed/multiple method
Evaluation
- Evaluate determinants of adoption of specific implementation strategies used by transformational coaches | - Insufficient information | - Individual interviews; - Focus groups separated by training/team role surveys; - Mixed/multiple methods; - Observation
Research type
- Continue inclusion of qualitative studies | - Insufficient information | - Longitudinal qualitative and quantitative studies to further understand the impact of coaching on QI and implementation

Abbreviation: QI=quality improvement

## CONCLUSIONS

Transformational coaching is a complex intervention that has the potential to support access to and use of data and technical resources for QI activities at the team and practice level. Transformational coaching, and other interventions with similar characteristics (ie, facilitation, outreach visitors), may have an effect on certain process of care activities, including composite process of care outcomes and ordering of labs and vital signs, and possibly on changes in organizational process of care and delivery of appropriate counseling. Differences among studies in the description and dosing of implementation strategies employed by coaches, as well as outcome measurement, precluded a more definitive estimate of effects. Specific strategies like adapting coaching techniques to team needs and preferences appears to be better received than other strategies. Future research that standardizes and provides more detail about how coaching interventions are used will better support future comparisons and implementation efforts.