# RESULTS

Note that the literature flow diagrams are provided separately under the respective Key Question heading.

## KEY QUESTION 1

1a What outcomes have been used to assess the effects of transformational coaching across practice, provider, and patient levels?
1b What are the effects of transformational coaching for team-based health care improvement and practice change efforts on process outcomes, specifically:
  - Adoption of targeted process of care activities (eg, more appropriate documentation of screening)
  - Quality improvement PROCESS goal attainment (eg, the number of quality improvement projects reaching completion)
  - Team member knowledge
  - Team member self-efficacy

### Literature Flow for KQ 1a and KQ 1b

For the KQ 1 search, we identified 2,609 articles through searches of MEDLINE^®^ (via Ovid^®^), EMBASE, and CINAHL (Figure 3). An additional 8 articles were identified through reviewing bibliographies of relevant review articles for a total of 2,617 articles. After removing duplicates, there were 1,753 articles. After applying inclusion and exclusion criteria to titles and abstracts, 99 articles remained for full-text review. Of these, 19 unique studies were retained for data abstraction. All 19 unique studies were cluster randomized trials. Included studies were conducted across North America, Europe, and Australia. One study was a VA study.

Figure 3 Literature Flow Chart: KQ 1a and KQ 1b

* Search results from MEDLINE (1001), Embase (503), CINAHL (241), and identified from relevant articles (8) were combined.

#### Key Points

- We identified 19 cluster-randomized trials (CRTs) that addressed the effects of transformational coaching on the process outcomes of interest; all but 1 trial were conducted within the primary care setting.
- Interventions typically targeted multiple simultaneous process of care activities requiring disparate clinical behaviors (eg, ordering a lab test, complicated patient counseling) but which were usually linked by a common goal (eg, improving management and outcomes for a specific disease).
- We found that coaching probably has a beneficial effect on composite process of care outcomes (n=7 trials) and ordering of labs and vital signs (n=5), and possibly has an beneficial effect on changes in organizational process of care (n=5), appropriate documentation (n=4) and delivery of appropriate counseling (n=2). It is uncertain if coaching has an beneficial effect on the conduct of specific exams and procedures (n=4), and probably does not have an effect on prescription of diagnosis appropriate medications (n=4).
- In 2 randomized trials, coaching interventions had no clear benefit for QI process goal attainment (ie, QI project initiation or achieving target goals).
- No trials specifically assessed team member knowledge or self-efficacy after coaching.

### Characteristics of Included Studies

Nineteen trials were included that address the effects of transformational coaching. Eleven were conducted in the United States,^18,38–47^ 4 in Europe,^48–51^ 3 in Canada,^52–54^ and 1 in Australia.^55^ All but 1 were conducted within the context of primary care or family medicine practices.^44^ The labels for the transformational coach-like role included practice facilitator, practice outreach facilitation, practice coach, nurse facilitator, nurse prevention facilitator, and outreach visitor. Some interventions meeting our inclusion criteria had more than 1 individual delivering the intervention and thus did not use a single term for the interventionist.^44,47^ Interventions varied in duration from 6 months to 36 months, and the coaching interventionists employed a variety of implementation strategies (see next section). In general, the number, disciplines, and roles of the interdisciplinary team members receiving the coaching intervention were not clearly described.

### Transformational Coaching Activities

Across the 19 included trials, we identified 13 distinct transformational coaching activities based on commonly used implementation strategies.^56^ Examples of specific transformational coaching activities mapped to Expert Recommendations for Implementing Change (ERIC) strategies^27^ are shown in Table 5.

Table 5 Transformational Coaching Activities

Coach-delivered Implementation Strategy | Operationalized Definition^a^ | ERIC Strategy Category | Examples from Included Studies
Baseline local need assessment (7 studies) | Collect and analyze data before the start of coaching intervention to assess local needs related to QI project | Use evaluative and iterative strategies | Performed a multimethod practice assessment, including assessment of practice communication, change and work culture, and level of implementation of the Chronic Care Model.^42^
Develop a formal implementation plan (18 studies) | Develop a formal implementation plan that includes clear goals and strategies | Use evaluative and iterative strategies | Group discussion to reflect on findings and identify priorities for improvement.^43^
Educational outreach visits (13 studies) | Coach meets with providers in their practice settings to educate about the clinical innovation | Train and educate stakeholders | Training: study staff conducted an in-person, 6-hour training with each subteam on how to use Get To Outcomes plan, implement, evaluate.^44^
Develop/distribute educational materials (14 studies) | Provide manuals, toolkits, and other supporting materials to teams | Train and educate stakeholders | Coaches introduced the concept of the Chronic Care Model and presented an evidence-based “toolkit”
Coach-delivered Implementation Strategy | Operationalized Definition^8^ | ERIC Strategy Category | Examples from Included Studies
| | | comprised of 5 activities to improve diabetes outcomes.^43^
Teach and support implementation/QI tools (7 studies) | Introduce and train teams on QI techniques and tools appropriate to the innovation or QI project being implemented | Use evaluative and iterative strategies | Education on “fostering a continuous QI culture.”^39^ Used the Chronic Care Model: the QI approach.^52^
Revise professional roles (8 studies) | Shift and revise roles among professionals who provide care, and redesign job characteristics | Support clinicians | A “lead physician” for liaising with the facilitator was identified in the practice.^53^
Technical assistance (7 studies) | Provide technical assistance (eg, data support) focused on QI project needs | Provide interactive assistance | MISSION-Vet service data was collected with a Computerized Patient Record System note template that was developed for each team. Data from the notes were extracted to create feedback reports.^44^
Develop resource sharing (4 studies) | Develop partnerships with organizations that have resources needed to implement the innovation | Support clinicians | Enhanced community linkage; “community resources.”^52^
Create a learning collaborative^b^(5 studies) | Facilitate the formation of groups of providers or provider organizations and foster a collaborative learning environment to improve implementation of the clinical innovation | Train and educate stakeholders | The learning sessions provided an opportunity for practice members to share successes and challenges with other practices.^42^
Organize clinician team meetings (3 studies) | Develop and support team meetings to structure protected time to reflect on the implementation effort, share lessons learned, and/or support one another’s learning | Develop stakeholder interrelationships | All practices were encouraged to initiate or increase routine staff meetings.^43^
Partner with local leadership (2 studies) | Create and engage a formal group of multiple levels of stakeholders (eg, local leadership) to provide input and advice on QI/implementation efforts and to elicit recommendations for improvements | Develop stakeholder interrelationships | Get administrative buy-in.^39^ Work with opinion leaders and encourage networking.^54^
Audit and feedback^c^(17 studies) | Collect and summarize clinical performance data over a specified time period and provide it to clinicians and administrators to monitor,evaluate, and modify provider behavior | Use evaluative and iterative strategies | Written feedback and practice-based discussion of clinical record audit of recording and levels of behavioral and physiological risk factors.^55^
Ongoing consultation (10 studies) | Provide ongoing consultation to support maintenance of QI project or innovation | Train and educate stakeholders | The facilitator gradually transfers various tasks to an interested member of the team. The practices also meet without the facilitator to further customize their work.^50^

a Operationalized definitions were modified from the ERIC strategy taxonomy.

b Studies with a learning collaborative were only included if the collaborative was not longitudinal and was only a minor part of the overall coaching-like intervention.

c Audit and feedback are considered 2 separate strategies,^57^ though in many included studies they were described together.

Abbreviations: QI=quality improvement

Within the context of coaching interventions, the 3 most commonly used coach-delivered implementation strategies were to develop a formal implementation plan (18/19), audit and provide feedback (17/19), and develop/distribute educational materials (14/19). The least-used strategies were organizing clinician team meetings (3/19) and developing stakeholder interrelationships (2/19) (Figure 4). Since the included trials were not necessarily designed as implementation studies, many do not have the degree of specificity ideally reported for implementation strategies.^58^ Within each of these groups of coaching activities, there was also diversity of duration and/or intensity of the intervention, composition and training of the intervention delivery team, mode(s) of delivery for the intervention, target(s) of the intervention, and outcomes addressed. The specific implementation strategies utilized in each of the included trials are in Appendix C.

Figure 4 Coach-delivered Implementation Strategies

### Detailed Findings: KQ 1a

Across the 19 included trials that evaluated effectiveness of transformational coaching, we mapped their included outcomes across practice, provider, and patient levels (Table 6). Five trials included outcomes at the practice level with measures addressing care delivery style, practice organization, culture, practice management, number of QI projects initiated, and QI objectives met.^43,44,49–51^ Fifteen trials included measures at the provider level.^18,38–42,45–49,51,53–55^ Measures at the provider level generally included guideline-concordant actions taken by providers during the delivery of disease specific or prevention related care delivery. Six trials created composite measures of groups of guideline-concordant actions as the outcome of interest.^18,38,42,52–54^ Clinical process of care actions at the provider level were almost exclusively measured via medical record review. No trials measured team member satisfaction with coaching experience, team member knowledge, or team member self-efficacy. One provider-level outcome measured provider confidence in ability to assess specific cardiovascular risk factors.^55^ Outcomes measures at the patient level were almost exclusively medical record based assessment of clinical outcomes (eg, achieving target blood pressure). One study measured patient self-reported satisfaction with diabetes treatment.^48^ Note that because this KQ was to map the outcomes and not evaluate effectiveness, there is no certainty of evidence assessment.

Table 6 Outcome Measures Used to Assess the Effect of Transformational Coaching by Practice, Provider, or Patient Levels

Study | Clinical Context | Outcome
Practice-level outcomes
Dickinson, 2014^42^ | Diabetes | Practice culture assessment; - Perceptions of practice characteristics important to practice function and implementation of QI
Parchman, 2013^43^ | Diabetes | Assessment of chronic illness care survey; - Extent to which care delivered in practice was consistent with elements of Chronic Care Model
Lobo, 2002^51^ | Cardiovascular preventive care | Aspects of practice organization:; - Availability of instruments and materials (eg, medical instruments, leaflets); - Presence of separate preventive clinics (eg, specific to diseases); - Teamwork in practice (eg, holding regularly scheduled meetings); - Record-keeping (eg, using computerized record, systematic recording of cardiovascular disease risk factors); - Follow-up activities (eg, make an appointment, provide an appointment card)
Engels, 2006^50^ | Primary Care | Dimensions of practice management; - Accessibility and availability (eg, time in minutes before practice picks up phone); - Medical care (eg, delegation of medical technician tasks); - Infrastructure (eg, lab facilities in practice); - Team (eg, meeting time with practice assistant in minutes); - Computerization (eg, electronic communication with hospital); - Quality and safety (eg, quality assurance in the practice); Number of projects initiated; Objectives met
Provider- and staff-level outcomes
Mold, 2014^40^ | Asthma | Adherence to 6 guideline recommendations:; - Assessment of asthma severity; - Assessment of environmental triggers; - Asthma action plan; - Assessment of level of control; - Asthma controller medications; - Asthma follow-up visits
Chinman, 2017^44^ | Implementation ofVAMISSION-Vet program by VA HUD-VASH case managers and peer specialists | Implementation measures:; - Adoption (case managers trying MISSION-VET); - Reach (patients received any Mission-VET sessions); - Dose MISSION-Vet received
Dickinson, 2019^38^ | Diabetes | Process of diabetes care elements (eg, hemoglobin A1c measurement, nutrition counseling); - Composite Score (0-9)
Carroll, 2018^39^ | Chronic kidney disease | - Avoidance of NSAIDs; - Use of ACEiand ARB; - Documentation of chronic kidney disease diagnosis
Harris, 2015^55^ | Chronic vascular disease prevention | Assessment in medical record of:; - Body mass index; - Waist circumference; - Systolic blood pressure; - Alcohol use; - Smoking status; - Cholesterol; - Fasting blood glucose; - Absolute cardiovascular risk; Self-reported frequency of assessment and confidence in above patient assessments by general practitioner
Meropol, 2014^41^ | Well-child visits at age 24-30 months | - Obesity screening and counseling; - Screening for lead toxicity; - Fluoride varnish application
Dickinson, 2014 ^42^ | Diabetes | Process of diabetes care elements (eg, hemoglobin A1c measurement, nutrition counseling); - Composite score (0-9)
Dickinson, 2019^38^ | Diabetes | Total number of self-management support activities (eg, collaborative goal setting, action planning around goals)
Rask, 2001^45^ | Diabetes | Receipt of diabetic screening services:; - HbA1c; - Blood pressure; - LDL cholesterol; - Nephropathy Diabetic eye exam Diabetic foot exam
van Bruggen, 2008^48^ | Diabetes | - Fasting blood glucose measured every 3 months; - Blood pressure measured every 3 months; - Bodyweight measured every 3 months; - ACEi/ARB agent prescribed according to guideline
Hogg, 2008^53^ | General primary prevention | - Composite index of preventive performance (# appropriate maneuvers/# inappropriate maneuvers/total # eligible maneuvers); - # appropriate maneuvers; - # inappropriate maneuvers
Goodwin, 2001^18^ | General primary prevention | - Global up-to-date score on receipt of recommended preventive services; - Screening preventive services delivery rate; - Counseling preventive services delivery rate; - Immunizations preventive services delivery rate
Lemelin, 2001^54^ | General primary prevention | - Overall index of preventive performance (proportion eligible patients receiving appropriate maneuvers-proportion eligible patients with inappropriate maneuvers); - Proportion recommended maneuvers done; - Proportion of inappropriate maneuvers done
Due, 2014^49^ | Chronic obstructive pulmonary disease; diabetes | - Change in # annual chronic disease check-ups per 100 patients (EHR & self-report); - Reduction number practices with <1% annual chronic disease check-ups per 100pts; - Change in # spirometry tests per 100 patients; - Sign-up to data capture software; - Changes in use of ICPC diagnosis coding for diabetes and COPD; - Changes in use of stratification of patients with diabetes and COPD
Margolis, 2004^46^ | General primary prevention | Change over time of proportion of children in each practice who received all four services (immunizations, screening for anemia, screening for lead, screening for tuberculosis)
Lobo, 2002^51^ | Cardiovascular preventive care | Preventive tasks performed by the practice assistant (eg, blood pressure measurements taken, cardiovascular history assessment, advice provided on smoking)
Ornstein, 2004^47^ | Cardiovascular preventive care | Percentage patients achieving clinical targets:; Hypertension:; - BP measurement in previous 12 months; - Diagnosis of hypertension for 3 BP measurements >/=140/90mm Hg; - BP measurement in 3 previous months in patients with hypertension; - Last BP measurement <140/90 mm Hg for all patients; - Last BP measurement <140/90 mm Hg for patients with hypertension; Hyperlipidemia:; - Cholesterol level in previous 60 months; - HDL cholesterol level in previous 60 months; - LDL cholesterol level in previous 12 months; - Diagnosis of hyperlipidemia for LDL cholesterol level >3.37 mmol/L (>130mg/dL); - Medication for LDL cholesterol level >3.37 mmol/L (>130mg/dL); Coronary heart disease:; - Prescription for beta blocker in patients with a history of MI; - Last LDL cholesterol level <2.59 mmol/L (<100 mg/dL); - Last BP measurement <140/90 mm Hg; Congestive heart failure:; Prescription for ACE inhibitor for ARB; Atrial fibrillation:; Prescription for oral anticoagulant; Diabetes mellitus:; - HbA1c measurement in previous 12 months; - LDL cholesterol level in previous 24 months for patients with diabetes; - BP measurements in previous 3 months for patients with diabetes; - Last HbA1c level <7%; Last LDL cholesterol level <2.59 mmol/L (<100 mg/dL) for patients with diabetes
Patient-level outcomes
Carroll, 2018^39^ | Chronic kidney disease | - CKD progression/annualized loss of eGFR; - Change in systolic blood pressure over time; - All-cause mortality (only in protocol)
Liddy, 2015^52^ | Cardiovascular disease | Adherence to recommended guidelines for cardiovascular disease processes of care:; - Blood pressure; - Lipid profile; - Waistline measure; - Smoking status; - Glycemic levels; - Kidney function; - Prescription of all eligible medications; - Referral to smoking cessation program
Dickinson, 2019^38^ | Diabetes | - HbA1c; - Systolic/diastolic pressure; - Body mass index
van Bruggen, 2008^48^ | Diabetes | Clinical targets:; - HbA1c; - Blood pressure; - Cholesterol; - Body mass index Diabetes Treatment Satisfaction questionnaire
Rask, 2001^45^ | Diabetes | Achievement of clinical targets:; - Blood pressure control; - LDL control; - HbA1c control
Harris, 2015^55^ | Chronic vascular disease prevention | Change in risk factors under control:; - Body mass index; - Waist circumference; - Systolic blood pressure; - Alcohol use; - Smoking status; - Cholesterol; - Fasting blood glucose; - Absolute cardiovascular disease risk

Abbreviations: ACEi/ARB=angiotensin converting enzyme inhibitor/angiotensin receptor blocking; BP=blood pressure; COPD=chronic obstructive pulmonary disease; eGFR=estimated glomerular filtration rate; HbA1c=glycated hemoglobin; ICPC=international classification of primary care; LDL=low-density lipoprotein; NSAID=nonsteroidal anti-inflammatory drug

### Detailed Findings: KQ 1b

We organize findings by the 4 a priori identified outcomes of most importance to our stakeholders. Specifically, we reviewed the effect of transformational coaching-like interventions on: (1) adoption of targeted process of care activities, (2) QI process goal attainment (eg, the number of QI projects reaching completion), (3) team member self-efficacy, and (4) team member knowledge. Due to the wide range of outcomes measured for uptake of targeted process of care activities, we grouped findings for that outcome by complexity of behavior required to conduct a given process of care activity, giving preferential attention to primary outcomes and trials judged to have a low risk of bias (ROB).

### Adoption of Targeted Process of Care Activities

#### Composite Outcomes of Multiple Clinical Processes of Care Activities

Seven trials explored the effects of transformational coaching on composite outcomes by measuring groups of guideline-concordant behaviors (Table 7).^18,38,42,46,52–54^ Of these, 4 trials focused on national guidelines for general preventive care activities,^18,46,53,54^ 2 focused on aspects of diabetes care,^38,42^ and 1 focused on CVD management.^52^ For all but 1 of these trials,^38^ the process of care composite outcome was the primary outcome for the study. Two trials were found to have low ROB,^46,53^ 4 unclear ROB,^18,38,52,54^ and 1 high ROB.^42^

##### National preventive care guidelines

Of the 4 trials focused on implementation of national preventive guidelines, 2 had overlapping authorship and similar methodologic approaches to assessing the implementation of Canadian Task Force on Preventive Health Care guidelines.^53,54^ The primary outcome for each was a composite index of preventive performance that factored in the conduct of desired preventive actions and commission of undesirable actions. Hogg and colleagues (2008) conducted a low ROB trial comparing 11.5 months of coaching with control among 54 fee-for-service primary care practices in Ontario, Canada.^53^ Authors reported a nonsignificant mean difference of 2.0 (95% CI −3.2 to 7.3) in the number of patients with the appropriate preventative maneuver documented in the health record.

The second study by Lemelin and colleagues (2001) was an unclear ROB trial that randomized 46 health service organizations in Ontario to 18 months of coaching or usual care.^54^ They found a change of mean percent patients receiving eligible preventive services from baseline to end of intervention of 31.9% to 43.2% in the intervention arm and 32.1% to 31.9% in the control arm (between-arm difference 11.5%; p <0.001). Of note, the coaching interventions in these 2 trials used somewhat different sets of coaching implementation strategies as shown in Table 7. In addition to goal setting/action planning, audit and feedback, toolkit provision, and ongoing maintenance support used by both interventions, 1 study also employed stakeholder engagement, informatics assistance, and academic detailing.^54^ The other study noted attention to role identification in addition to the common 4 strategies.^53^

The third study of preventive services implementation was a low ROB trial by Margolis and colleagues (2004) that compared a 12-month coaching intervention with an undefined control condition among 44 private pediatric and family practices in North Carolina.^46^ Authors examined the conduct of 4 desired preventive processes of care for pediatric patients between 24 and 30 months of age (ie, anemia, lead, and tuberculosis screening, and completion of immunization schedule). At 18 months (6 months after end of intervention), the proportion of children receiving all services was 17% in the intervention practices compared with 10% in the control practices, which amounted to a ratio of change from baseline of 2.5 for intervention and 1.0 for control (with a ratio of intervention vs control at 2.4; 95% CI 0.9 to 6.5). While not significant at 18 months, by 30 months the ratio of proportional change from baseline for intervention versus control was 4.6 (95% CI 1.6 to 13.2).

The fourth study was an unclear ROB trial by Goodwin and colleagues (2001) that compared the effect of a 12-month coaching intervention to an unspecified control arm on implementation of the US Preventive Services Task Force’s preventive guidelines.^18^ Authors reported a significant end of intervention difference for implementation of screening, counseling, and immunization guidelines with 42.4% of 38 intervention primary practices compared with 37.2% of 39 control practices (adjusted p<0.001).

##### Diabetes processes of care

Of the 2 trials addressing improvements in diabetes processes of care, 1 was judged unclear ROB^38^ and the other was judged high ROB for objective outcomes and unclear ROB for subjective outcomes.^42^ In the first study, Dickinson and colleagues (2019) randomized 36 primary care practices to 1 of 3 implementation strategies to increase self-management support for patients with diabetes (education only; education plus access to an evidence-based interactive behavior-change technology program; or education plus program plus brief coaching intervention).^38^ The total number of self-management support activities by patient chart documentation (a secondary outcome) increased from baseline to end of intervention for the coaching arm compared with the education-only control (7.68 vs 4.58; p=0.0013). A mediator analysis showed a nonsignificant difference between the slopes for coaching and education arms related to change in hemoglobin A1c (primary outcome) over time.

In the second study, Dickinson and colleagues (2014) evaluated the effects of 2 different types of coaching (based on reflective adaptive process and continuous QI approaches) compared with enhanced usual care on adherence to 9 items of care recommended by the American Diabetic Association.^42^ Among 40 primary care practices (822 patients), the authors found all 3 arms improved by end of intervention; however, the coaching arm based on continuous quality improvement (CQI) arm experienced greater improvement in process of care score (3.58 to 4.91; p<0.0001) than either the reflective adaptive process (4.54 to 4.85) or the enhanced usual care arm (3.63 to 4.39; p <0.0001).

##### Cardiovascular disease management

The final study was an unclear ROB trial by Liddy and colleagues (2015) that was a pragmatic stepped-wedge CRT evaluating the effects of 24 months of coaching intervention on mean adherence to cardiovascular disease process of care guidelines (8 clinical indicators).^52^ Across 84 primary care practices (5292 patients), authors found an absolute decrease in mean adherence of 4.2% (95% CI −5.7% to −2.6%) at Year 2.

Bottom Line

Of the 7 trials that assessed the effect of coaching interventions on composite process of care outcomes, 6 were low or unclear ROB and 1 was high ROB. Five favored the intervention (83%; 95% CI 36% to 99%). The probability of observing 83% of trials with a beneficial effect if coaching interventions are truly ineffective is p=0.22. Two of the 7 trials were low ROB, and 1 of these favored the intervention at the end of intervention time point.^53^ The other low ROB study did not provide a comparison to baseline at end of intervention but did find a significant effect favoring the intervention at 18 months, which continued to increase up to 36 months.^46^

Table 7 Effects of Transformational Coaching on Composite Outcomes

Study; N Unit of Randomization | Duration of Intervention; Comparator | Outcome | Overall ROB | Available Data^a^ | Metric^b^
Hogg, 2008^53^; 54 primary care practices | 11.5 months; Usual Care | (Number of appropriate preventive maneuvers minus inappropriate) divided by total eligible maneuvers | Low | MD 2.0 (95% CI −3.2 to 7.3) | 1
Margolis, 2004^46^; 44 pediatric/family practice clinics | 12 months; Undefined | Proportion of children with 4 preventive maneuvers (anemia/lead/tuberculosis screening, complete immunization schedule) | Low | – | –
Lemelin, 2001^54^; 46 health service organizations | 18 months; Usual care | (Number of appropriate preventive maneuvers minus inappropriate) divided by total eligible maneuvers | Unclear | MD 11.5(p<0.001) | 1
Goodwin, 2001^18^; 77 primary care practices | 12 months; Undefined | Proportion of eligible prevention services received | Unclear | 42.4% vs 37.2 %; p<0.01 | 1
Dickinson, 2019^38^; 36 primary care practices | 18 months; Education only | Total number of diabetes self-management support activities documented^c^ | Unclear | 7.68 vs 4.58; p=0.0013 | 1
Liddy, 2015^52^; 84 primary care practices | 24 months; Stepped wedge | Mean adherence to 8 clinical indicators for cardiovascular care | Unclear | MD −4.2% (95% CI −5.7 to −2.6); P < 0.0001 | 0
Dickinson, 2014^42^; 40 primary care practices | 12 RAP/18 CQI months^d^; Enhanced usual care | Receipt of 0-9 diabetes process of care items | High | (RAP) 4.54→4.85; (CQI) 3.58→4.91; (EUC) 3.63→4.39; EUC vs RAP p=0.03; CQI vs EUC p<0.0001; CQI vs RAP p<0.001 | 1 (CQI only)

a When available data are provided, intervention is always listed before comparator.

b For values in metric column: 1 = beneficial effect, 0 = no effect/harmful; Values based on direction of effect without consideration of magnitude of effect or statistical significance

c Secondary outcome.

d For the 2 coaching intervention arms: reflective adaptive process-based coaching was 6 months with up to 12 months of consultation; continuous quality improvement-based coaching was 18 months.

Abbreviations: CI=confidence interval; CQI=continuous quality improvement; EUC=enhanced usual care; MD=mean difference; RAP=reflective adaptive process; ROB=risk of bias

##### Organizational Processes of Care

Five trials explored transformational coaching interventions aimed at improving organizational structures related to clinical processes of care,^43,44,49–51^ which was a primary outcome for all but 1 study.^50^ Parchman and colleagues (2013) conducted a low ROB stepped-wedge trial to examine the effect of a 12-month coaching intervention on the extent to which 40 small primary care practices delivered their diabetes care using the chronic care model.^43^ This study described the most implementation strategies across this subgroup focused on organizational processes, with 10 employed by their coaching intervention (Table 8). After 12 months of a coaching intervention, they found significant within-group improvement of adherence to chronic care model principles as measured by the chronic illness care survey at the end of the intervention (mean difference 0.75; 95% CI 0.09 to 1.40), but the between-group effect was not significant.

Lobo and colleagues (2002) conducted a low ROB trial testing the ability of a 21-month coaching intervention to improve the organizational deficiency score of adherence to 6 aspects of preventive cardiovascular care (eg, teamwork in the practice, availability of instruments and materials) across 124 primary care practices in the Netherlands.^51^ Compared to a “no stimuli” control arm, the intervention arm had a significantly greater reduction in all organizational deficiency scores (p<0.001).

The other 3 trials were at unclear ROB. One by Engels and colleagues (2006) studied the effect of a 12-month intervention using a continuous QI framework on practice management as a secondary outcome.^50^ There were no significant differences between 26 interventions and 23 usual care control primary care practices on 20 dimensions of practice management, though the direction of effect favored intervention in 12 of the 20 dimensions. The second trial at unclear ROB was conducted in Denmark by Due and colleagues (2014) using a stepped-wedge design to study the effect of coaching on the implementation of disease management programs for chronic obstructive pulmonary disease and type 2 diabetes mellitus. Authors found no difference in the change in annual chronic disease check-ups per 100 patients (primary outcome).^49^ The third trial, from Chinman and colleagues (2017), was a VA-based CRT that measured the impact of the Getting to Outcomes (GTO) strategy for implementing an evidence-based practice, in this case the MISSION-Vet treatment model for Veterans with a history of homelessness and co-occurring substance use disorder.^44^ The unit of randomization was the Department of Housing and Urban Development–Veterans Affairs Supportive Housing (HUD-VASH) subteam. While not delivered by a single person or coach, the components of the GTO intervention met our criteria for inclusion collectively and used a total of 6 implementation strategies. Because this was a hybrid type III study, the relevant primary outcomes were implementation outcomes of adoption and reach. Authors found a significant improvement in reach (ie, the percentage who received any MISSION-VET sessions) from 0% to 7% in the implementation arm compared with the control arm 0% (p<0.05), and adoption (ie, the percentage of case managers trying MISSION-VET) from 0% to 68% versus 0% to 0% (p<0.05).

Bottom Line

Of the 5 trials that assessed the effect of coaching on organizational process of care outcomes, 4 favored the interventions (80%; 95% CI 28% to 99%; p >0.99). If we consider the study by Engels and colleagues to favor no effect, this drops to 3 of 5 or 60% (95% CI 15% to 95%).^50^ Both low ROB trials favored the coaching intervention.

Table 8 Effects of Transformational Coaching on Organizational Processes of Care

Study; N Unit of Randomization | Duration of Intervention; Comparator | Outcome (Scale Details) | Overall ROB | Available Data | Metric
Parchman, 2013^43^; 40 primary care practices | 12 months; Stepped wedge | Mean adherence to chronic care model principles (assessment of chronic illness care survey; 0-11 on each of 6 subscales) | Low | MD 0.75 (95% CI 0.09 to 1.40; p=0.02) | 1
Lobo, 2002^51^; 124 primary care practices | 21 months; Usual care | Change in deficiency score across 6 aspects of practice organization (ie, availability of instruments/materials, teamwork in practice) | Low | Favors coaching for all 6 aspects; p<0.001 | 1
Engels, 2006^50^; 49 primary care practices | 12 months; Usual care | 20 dimensions of practice management^a^ | Unclear | All 20 dimensions of practice management nonsignificant, though direction favors intervention in 12 dimensions | 0/1
Due, 2014^49^; 189 primary care practices | 9 months; Stepped wedge | Change in annual chronic disease check-ups per 100 patients | Unclear | Median (IQR):; Coaching 0.5 (0.0 to 1.9); Delayed 0.5 (0.0 to 1.3); p=0.1639 | 0
Chinman, 2017^44^; 69 housing services subteam | 12-23 months; Usual implementation | Adoption (% case manager implementing any MISSION-Vet); Reach (% Veterans receiving any MISSION-Vet sessions) | Unclear | Coaching vs comparator: Adoption; 0→68% vs 0→0%; p<0.05; Reach; 0→7% vs 0→0%; p<0.05 | 1

a Secondary outcome.

Abbreviations: CI=confidence interval; MD=mean difference; IQR=interquartile range

##### Appropriate Documentation

Four trials evaluated the effect of transformational coaching on appropriate medical record documentation (Table 9).^39,40,47,55^ The study by Mold and colleagues (2014), judged to have unclear ROB, examined implementation of 6 key guideline-concordant asthma recommendations in 45 primary care practices randomized to 1 of 4 six-month interventions: transformational coaching, a local learning collaborative, coaching plus collaborative, and enhanced usual care (eg, performance feedback, academic detailing, guideline summaries, and a toolkit).^40^ Five of 6 guidelines measured were related to documentation (ie, asthma severity, level of control assessment, triggers, follow-up visit plan, and action plan). There was no difference between the enhanced usual care and transformational coaching arms for documentation of asthma triggers, follow-up visit plan, or action plan (p=0.58, 0.83, and 0.24, respectively; no odds ratios given), though in a matched-pair analysis within the transformational coaching arm, assessment of asthma triggers was significantly improved from 42% preintervention to 57% postintervention. Both assessment of level of asthma control (n=937) and asthma severity (n=977) were found to have significant preintervention-to-postintervention increases when compared to control, with odds ratios (ORs) of 2.3 (95% CI 1.5 to 3.5) and 2.5 (95% CI 1.7 to 3.8), respectively.

The other 3 trials that assessed documentation after a coaching intervention were judged to have high ROB.^39,47,55^ One by Harris and colleagues (2015) measured documentation of cardiovascular disease risk, alcohol use, and smoking assessment across 32 practices before and after a 6-month practice facilitation intervention compared to an undefined control.^55^ All 3 findings were significant, with ORs ranging from 1.50 (95% CI 1.04 to 2.18) to 2.24 (95% CI 1.17 to 4.29). Ornstein and colleagues (2004) studied a 24-month multi-method QI intervention compared to enhanced usual care (ie, quarterly practice performance reports) on 21 quality indicators for primary and secondary prevention of cardiovascular disease across 23 US primary care practices.^47^ Two of the 21 performance targets for this trial were related to documentation (ie, documented diagnosis of hypertension for 3 blood pressure recordings >140/90; diagnosis of hyperlipidemia for low-density lipoprotein >130). Authors found mixed results with an adjusted difference in improvement of percent-eligible patients at target of 15.7 (95% CI 5.2 to 26.3) for hypertension diagnosis and 11.3 (95% CI −5.9 to 28.5) for hyperlipidemia. The third high ROB study, by Carroll and colleagues (2018) randomized 42 primary care practices to either electronic health record (EHR)-based clinical decision support (CDS) alone or CDS plus transformational coaching to support implementation of guideline-concordant care of patients with chronic kidney disease (CKD).^39^ Documentation of CKD diagnosis was a secondary outcome and there was no significant difference between arms.

Bottom Line

Of the 4 transformational coaching models that assessed the effect on appropriate documentation, 3 included outcomes that favored the interventions (75%; 95% CI 0.19 to 99%; p=0.625). There were no low ROB trials in this subgroup.

Table 9 Effects of Transformational Coaching on Appropriate Documentation

Study; N Unit of Randomization | Duration of Intervention; Comparator | Outcome | Overall ROB | Available Data | Metric
Mold, 2014^40^; 45 primary care practices | 6 months; Enhanced usual care | 5 of 6 asthma guideline targets (ie, asthma severity, level of control assessment, triggers, follow-up visit plan, and action plan) | Unclear | Nonsignificant for triggers, follow up, action plan Levelcontrol OR 2.3 (95% CI 1.5 to 3.5) Severity OR 2.5 (95% CI 1.7 to 3.8) | −/1
Harris, 2015^55^; 32 primary care practices | 6 months; Undefined | Assessment of cardiovascular risk, alcohol use, smoking status | High | CVD:OR 1.50(95%CI 1.04 to 2.18) Alcohol use: OR 2.19 (95% CI 1.04 to 4.64) Smoking: OR 2.24 (95% CI 1.17 to 4.29) | 1
Ornstein, 2004^47^; 23 primary care practices | 24 months; Enhanced usual care | 2 of 21 performance targets related to primary and secondary cardiovascular prevention (diagnosis of HTN for SBP >140/90 × 3; hyperlipidemia for LDL >130) | High | Adjusted difference in improvement (HTN) 15.7 (95% CI 5.2 to 26.3); p<0.001 (HL) 11.3 (−5.9 to 28.5); p>0.2 | 1
Carroll, 2018^39^; 42 primary care practices | 36 months; EHR Clinical decision support | CKD diagnosis on problem list^a^ | High | Adjusted model coefficient: −0.04 (SE 0.06); p=0.46 | 0

a Secondary outcome.

Abbreviations: CKD=chronic kidney disease; CI=confidence interval; CVD=cardiovascular disease; LDL=low-density lipoprotein; HL=hyperlipidemia; HTN=hypertension; OR=odds ratio; SE=standard error; SBP=systolic blood pressure

##### Appropriate Medication Prescription

Four trials measured the effect of transformational coaching on the prescription of disease-appropriate medications (Table 10).^39,40,47,48^ The unclear ROB study by Mold and colleagues (2014) also measured the provision of asthma controlled medications; however, there was no difference between the enhanced usual care and transformational coaching arms (p=0.24) or within the transformational coaching arm in a matched-pair analysis.^40^

A study judged to have unclear ROB by van Bruggen and colleagues (2008) employed a 12-month coaching intervention across 30 primary practices and found no difference in prescription of ACE-i or ARB among patients with diabetes (p=0.6).^48^

The previously described high ROB pragmatic CRT by Carroll and colleagues (2018)^39^ found that neither of the relevant secondary outcomes—use of ACE-i/ARB and avoidance of nonsteroidal anti-inflammatory drugs—was significantly improved in the coaching arm compared with the comparator.

The high ROB study by Ornstein and colleagues (2004) measured 4 of 21 performance targets related to medication prescription for the following conditions: coronary heart disease (ie, beta-blockers, cholesterol medication), congestive heart failure (ie, angiotensin converting enzyme inhibitors [ACE-i], angiotensin-receptor blockers [ARB]), and atrial fibrillation (ie, anticoagulants).^47^ Authors found no significant effect across these performance targets measured by percent-adjusted difference in improvement ranging from −7.1 to 6.5 (all p values >0.17).

Bottom Line

Of the 3 studies that allowed assessment of the direction of effect on appropriate medication prescription, 2 included at least 1 outcome that favored the coaching interventions (66%; 95% CI 9% to 99%; p >0.99). There were no low ROB trials in this subgroup, and neither of the unclear ROB trials showed a statistically significant difference.

Table 10 Effects of Transformational Coaching on Appropriate Medication Prescription

Study; N Unit of Randomization | Duration of Intervention; Comparator | Outcome | Overall ROB | Available Data | Metric
Mold, 2014^40^; 45 primary care practices | 6 months; Enhanced usual care | 1 of 6 asthma guideline targets (ie, asthma controller medication) | Unclear | Nonsignificant | –
Van Bruggen, 2008^48^; 30 primary care practices | 12 months; Usual care | ACEi/ARB for type 2 diabetes^a^ | Unclear | 67.4% vs 65.1%; nonsignificant; p=0.6 | 0
Ornstein, 2004^47^; 23 primary care practices | 24 months; Enhanced usual care | 4 of 21 performance targets related to primary and secondary cardiovascular prevention (beta-blocker and cholesterol medication for CAD, ACEi/ARB for CHF, anticoagulation for AF) | High | Adjusted difference in improvement: Beta-blocker: 6.5 (95% CI −17.1 to 30.0; p>0.2) Cholesterol: 1.6 (95% CI −12.4 to 15.5; p;0.2) ACEi/ARB: 2.0 (95% CI −8.2 to 12.3; p>;0.2)Anticoagulation: −7.1 (95% CI −17.7 to 3.6; p=0.171) | 1/0
Carroll, 2018^39^; 42 primary care practices | 36 months; EHR clinical decision support | Use of ACEi/ARB and avoidance of NSAIDs among patients with chronic kidney disease^a^ | High | Adjusted model coefficient (ITT) NSAID: 0.42 (SE 0.34); p=0.22 ACEi/ARB: −0.52 (SE 0.47); p=0.27 | 1/0

a Secondary outcome.

Abbreviations: ACEi/ARB=angiotensin converting enzyme inhibitor/angiotensin-receptor blocker; AF=atrial fibrillation; CAD=coronary artery disease; CHF=congestive heart failure; CI=confidence interval; NSAID=nonsteroidal anti-inflammatory drug; SE=standard error

##### Appropriate Counseling

We identified 2 low ROB trials that addressed the effect of transformational coaching on providing appropriate counseling (Table 11).^41,51^ Meropol and colleagues (2014) examined the effect of a 6-month coaching intervention on improving 3 prevention measures, 1 of which was pediatric obesity screening and counseling for 35 primary care practices.^41^ Practices were randomized to either early-phase or late-phase (control) of the intervention. For obesity screening/counseling, the coaching intervention was associated with large improvements in all practices; obesity screening/counseling rose from 3.5% to 82.8.% in early-phase and from 6.3% to 12.2% in late-phase practices (p<0.001) at 4 months (before the late phase received the intervention) as measured by well-child visit chart reviews.

Lobo and colleagues (2002) tested the ability of a 21-month coaching intervention in 124 primary care practices in the Netherlands to improve the organizational deficiency score of preventive cardiovascular care. One subcomponent of the primary outcome was percent of practices with the practice assistant giving advice on diet, smoking, weight loss, exercise, and alcohol use.^51^ For these counseling on these 6 aspects of preventive cardiovascular care, the intervention groups showed a range of absolute increase in percent adherence from 24 to 34 from baseline compared with 3 to 10 for the comparator (p <0.05).

Bottom Line

Both of the low ROB trials that assessed the effect of coaching on counseling provision favored the interventions (100%; 95% CI 16 to 100). For 1 study, this outcome was a subcomponent of the primary outcome.^51^

Table 11 Effects of Transformational Coaching on Appropriate Counseling

Study; N Unit of Randomization | Duration of Intervention; Comparator | Outcome | Overall ROB | Available Data | Metric
Meropol, 2014^41^; 31 pediatric practices | 6 months; Stepped wedge | Pediatric obesity screening and counseling (pre/post %) | Low | Coaching: 3.5/82.8 (95 % CI 76.1 to 87.9) Comparator: 6.3/12.2 (95% CI 8.2 to 17.8) p<0.001 | 1
Lobo, 2002^51^; 124 primary care practices | 21 months; Usual care | Advice given by practice assistant on diet, smoking, weight loss, exercise, alcohol (change in pre/post %) | Low | Coaching: 24–36 Comparator: 3–10 All p<0.05 | 1

Abbreviations: CI=confidence interval

##### Appropriate Provider Exams and Procedures

We identified 4 trials that assessed the effect of transformational coaching on appropriate provider exams and procedures (Table 12).^41,49,55^ The low ROB stepped-wedge study by Meropol and colleagues (2014) noted previously also examined the effect of its 6-month coaching intervention on improvement of fluoride application.^41^ The early-phase intervention had improvements from 0.01% to 89.1% compared with the late-phase control at 0.01% to 4.4% at 4 months (before the late phase started the intervention).

Rask and colleagues (2001) conducted an unclear ROB trial to test the ability of a 12-month coaching intervention to increase the rate at which diabetes patients receive guideline-concordant preventive services including foot and eye exams.^45^ The coaching intervention took place in 4 community-based primary care clinics, and practices were randomized to either a multifaceted coaching intervention or a feedback-only comparator. Following the coaching intervention, there were statistically significant increases in the documentation of foot examinations (p< 0.001) but not eye exams in the multifaceted intervention groups.

Due and colleagues (2014) conducted a stepped-wedged trial at unclear ROB to study the effect of coaching on the implementation of disease management programs for chronic obstructive pulmonary disease and type 2 diabetes mellitus and found no significant differences in the use of spirometry per 100 patients (p=0.0835).^49^

Last, Harris and colleagues (2015) conducted a high ROB CRT to evaluate the effect of a coaching intervention on improving implementation of guideline-concordant care for chronic vascular disease.^55^ The coaching intervention took place in 32 primary care practices in Australia and lasted 6 months. For the procedure of measuring waist circumference, risk recording improved in the intervention group (OR 2.52; 95% CI 1.30 to 4.91) but not in the control group.

Bottom Line

Of the 4 trials that assessed the effect of coaching on provision of appropriate exams or procedures, 3 included outcomes that favored the interventions (75%; 95% CI 19% to 99%). Both negative findings in this sensitivity analysis were from secondary outcomes.

Table 12 Effects of Transformational Coaching on Provider Exams and Procedures

Study; N Unit of Randomization | Duration of Intervention; Comparator | Outcome | Overall ROB | Available Data | Metric
Meropol, 2014^41^; 30 pediatric practices | 6 months; Stepped wedge | Application of fluoride during well-child visits aged12-35 months (pre/post%) | Low | Coaching: 0.1/89. Comparator: 0.1/4.4 p<0.001 | 1
Due, 2014^49^; 189 primary care practices | 9 months; Stepped wedge | Spirometry per 100 patients^a^ | Unclear | Median (IQR): Coaching 0.6 (0.2 to1.2) Delayed 0.5 (0.1 to 0.8) p=0.0835 | 0
Rask, 2001^45^; 4 primary care clinics | 12 months; Enhanced usual care | Diabetic eye/foot exam (pre/post %)^b^ | Unclear | Eye: Coaching: 11/13 Comparator: 22/13; Foot: Coaching: 5/32 Comparator: 33/29; Both nonsignificant | 0/1
Harris, 2015^55^; 32 primary care practices | 6 months Undefined | Waist circumference | High | OR 2.52 (95% CI 1.30 to 4.91) | 1

a Definite secondary outcome.

b Possible secondary outcome.

Abbreviations: CI=confidence interval; IQR=interquartile range; OR=odds ratio

##### Ordering Laboratory Tests and Vital Signs

Five trials explored transformational coaching interventions aimed at improving the ordering of laboratory tests and assessment of vital signs (Table 13).^41,45,47,48,55^ The third main outcome from the low ROB Meropol (2014) study was successful lead screening.^41^ For this outcome, the coaching intervention was associated with improvements in lead screening in the first 4 months (ie, early-phase practices receiving the intervention), with screening rising from 62.2% to 86.3%; however, screening fell in late-phase practices (ie, delayed intervention) from 77.8% to 70.9% (p<0.001).

The previously described study by Rask (2001), evaluated as unclear ROB, tested the ability of a 12-month coaching intervention to increase the rate at which diabetes patients receive guideline-concordant preventive services including glycosylated hemoglobin (HbA1c), low-density lipoprotein (LDL) cholesterol, blood pressure, and nephropathy screening.^45^ The multifaceted intervention increased the odds of receiving all 4 screening services compared to the control groups, but only the increase in HbA1c monitoring was statistically significant (OR 1.70; 95% CI, 1.08 to 2.68).

The trial by van Bruggen and colleagues (2008) was an unclear ROB CRT to assess the effects of a coaching intervention on the implementation of a locally adapted type 2 diabetes practice guideline in the Netherlands.^48^ The coaching intervention lasted 12 months, and the outcomes of interest (nonprimary outcomes) were every-3-month measurement of fasting blood glucose, blood pressure, and body weight. The coaching intervention arm had significantly higher levels of meeting these targets across all 3 outcomes compared with control in both unadjusted and adjusted analyses: 87.8% versus 68.6% for fasting blood glucose every 3 months (p<0.001); blood pressure every 3 months 82.5% versus 65.4% (p<0.01); and body weight every 3 months 82.5% versus 65.4% (p<0.001).

Two high ROB trials also addressed this type of process of care outcome. First, Ornstein and colleagues (2004) found no significant effect on adjusted difference in improvement of percent-eligible patients for any of the following 8 performance targets: cholesterol level in last 60 months, high-density lipoprotein level in the last 60 months, LDL cholesterol level in the previous 12 months, HbA1c in the last 12 months, LDL in the previous 24 months, blood pressure in last 12 months, or blood pressure in last 3 months. However, 5 of the 8 outcomes favored the intervention with wide confidence intervals. Finally, Harris and colleagues (2015) also evaluated the effect of coaching on improving implementation of guideline-concordant care for chronic vascular disease^55^ including body mass index, blood pressure, and lipids/fasting blood glucose. All reported odds ratios favored the intervention but were not statistically significant.

Bottom Line

Of the 5 trials that assessed the effect of coaching on ordering of labs or vitals, all included at least some outcomes that favored the interventions (100%; 95% CI 48% to 100%; p=0.0625). In a sensitivity analysis in which 2 trials were considered to have no evidence of beneficial effect, only 3 of 5, or 60% (95% CI 15% to 95%), favored coaching intervention.^45,47^

Table 13 Effects of Transformational Coaching on Ordering Lab Tests and Vital Signs

Study; N Unit of Randomization | Duration of Intervention; Comparator | Outcome | Overall ROB | Available Data | Metric
Meropol, 2014^41^; 31 pediatric practices | 6 months; Stepped wedge | Lead screening (pre/post %) | Low | Coaching: 62.2/86.3 (95% CI 77.4 to 92.0) Comparator: 77.8/70.9 (95% CI 56.8 to 81.9)^a^p0.001 | 1
Rask, 2001^45^; 4 primary care clinics | 12 months; Enhanced usual care | Screening for glycosylated hemoglobin (HbA1c), low-density lipoprotein (LDL), blood pressure, and nephropathy (4 of 6 targets; pre/post%) | Unclear | HbA1c: OR 1.70 (95% CI 1.08 to 2.68) LDL: 68/71 vs 63/64; nonsignificant BP: 80/95 vs 74/92; nonsignificant Nephropathy: 49/44 vs 58/43; nonsignificant | 1/0
van Bruggen, 2008^48^; 30 primary care practices | 12 months; Usual Care | Measurement of fasting blood glucose, weight, blood pressure every 3 months (post %) | Unclear | Blood glucose: 87.8 vs 68.6; p<0.001 Weight: 82.5 vs 65.4; p<0.01 BP: 78.9 vs 48.5; p<0.001 | 1
Ornstein, 2004^47^; 23 primary care practices | 24 months; Enhanced usual care | 8 of 21 performance targets related to primary and secondary cardiovascular prevention (cholesterol level in last 60 months, HDL level in last 60 months, LDL level in previous 12 months (CHD), a1c in last 12 months (DM), LDL cholesterol level in previous 24 months, BP in last 12 months, BP in last 3 months (HTN/DM)) | High | Adjusted difference in improvement Cholesterol: 0.2 (95% CI −12.0 to 12.4) HbA1 c: 5.8 (95% CI −10.0 to 21.6) BP: 3.2 (−4.2 to 10.7) BP (HTN): 6.7 (95% CI −1.0 to 14.4) BP (DM): 5.0 (95% CI −4.6 to 14.7) HDL:−1.9 (95% CI −8.4 to 12.2) LDL (CHD): −11.0 (95% CI −23.0 to 1.0) LDL (DM): −1.9 (95% CI −13.8 to 9.9) | 1/0
Harris, 2015^55^; 32 primary care practices | 6 months; Undefined | Measurement of BMI, blood pressure, cholesterol | High | BMI: OR 1.28 (95% CI 0.87, 1.88) BP: OR 1.12 (95% CI 0.79, 1.58) Cholesterol: OR 1.29 (95% CI 0.88, 1.91) | 1

a Results are from the 4-month assessment with early-phase as coaching compared with late-phase coaching intervention as the comparator.

Abbreviations: BMI=body mass index; BP=blood pressure; CHD=coronary heart disease; CI=confidence interval; DM=diabetes mellitus; HbA1c= glycosylated hemoglobin; HDL=high-density lipoprotein; HTN=hypertension; LDL=low-density lipoprotein

### QI Process Goal Attainment

We identified 2 trials that addressed the effect of transformational coaching on goal attainment. The first, by Engels and colleagues (2006), was a CRT at unclear ROB studying the effect of a 12-month continuous QI-based intervention on practice management in 49 primary care practices in the Netherlands.^50^ Compared with usual care (ie, feedback and suggestions from a standard practice management assessment required for accreditation), the intervention arm initiated more QI projects during the intervention, with a mean of 3.9 QI projects per practice versus 2.6 (p<0.001). As a secondary outcome, intervention practices were more likely to meet their self-defined objectives for 80% of their projects than were usual care practices (80% vs 69%; p<0.001).

The second study, by Ornstein and colleagues (2004), was a high ROB CRT evaluating the effect of a 24-month multi-method QI intervention compared with enhanced usual care (ie, quarterly practice performance reports) on 21 quality indicators for primary and secondary prevention of cardiovascular disease (CVD) across 23 US primary care practices.^47^ Of note, the intervention in this study was delivered by more than 1 person. For the primary practice-level outcome, authors found that there was no significant difference between the intervention and control practices in the percentage of mean indicators at or above target (p>0.2). Both arms had a significant within-group increase by 24 months, with the intervention arm increasing from 11.3% to 33.7% (p=0.02) and the control group from 6.3% to 22.7% (p=0.027).

Bottom Line

There were mixed results on the effect of transformational coaching interventions on QI process goal attainment across only 2 relevant studies. The 1 unclear ROB study with 49 sites found a significant increase in the number of QI projects per practice in the intervention versus the comparator arms (primary outcome).^50^

### Team Member Knowledge

No trials addressed the effect of transformational coaching or similar roles on team member knowledge.

### Team Member Self-efficacy

While we identified no studies that directly addressed self-efficacy of team members related to the practice of QI methods or skills related to a specific QI project after interaction with a transformational coach, the high ROB study by Harris and colleagues (2015) addressed a similar construct as a secondary outcome.^55^ Authors evaluated confidence in the ability to assess 6 patient lifestyle behaviors important for prevention of chronic vascular disease: smoking status, nutrition, risky drinking, physical activity, readiness to change, and absolute risk for CVD. The study measured these areas of self-confidence among 97 primary care providers across 32 practices before and after a 6-month practice facilitation intervention compared to an undefined control. Only 2 areas showed significant improvement among intervention providers compared to control: assessment of a patient’s readiness to change and absolute CVD risk. The percentage of providers reporting being very confident (5 on a 5-point Likert scale) increased by 14.3% on readiness to change for intervention compared with a decrease of 9.8% in the control group (p=0.04), and +16.0% for absolute CVD risk for the intervention compared with −7.3% for the control group (p=0.03).

Bottom Line

No trials directly addressed team member self-efficacy. One high ROB trial found statistically significant improvement in provider confidence in assessment of 2 of 6 CVD lifestyle behaviors post-intervention.

### Quality of Evidence for Key Question 1b Studies

For the 19 CRTs, the ROB was judged to be low for 6 studies,^41,43,46,50,51,53^ unclear for 9 studies,^18,38,40,44,45,48,49,52,54^ and high for 4 studies.^39,42,47,55^ Patterns that led to higher ROB included differences in baseline patient (n=3)^39,42,45^ and practice characteristics (n=3),^46,54,55^ attrition/incomplete outcome assessment (n=4),^39,42,47,55^ detection bias for patient-reported outcomes (n=2),^49,55^ protection against contamination (n=2),^44,49^ and missing information about statistical compensation for effect of cluster randomization (n=6).^38,40,45,49,53,54^ Multiple studies were missing clear details about both practice- and patient-level characteristics. In addition, multiple studies did not include enough detail about the randomization mechanism and allocation concealment to fully determine the level of ROB. Risk of bias ratings are shown for each study in Figure 5 and across all studies in Figure 6.

Figure 5 Risk of Bias Assessment for Included Studies in KQ lb

Figure 6 Risk of Bias Assessment Across Included Studies (n=19) in KQ 1b

### Certainty of Evidence for Key Question 1b

The certainty of evidence as determined through assessment of GRADE criteria for the effect of transformational coaching is shown in Table 14. Note that there is no certainty of evidence evaluation for KQ 1a because it mapped outcomes rather than determined effect.

Table 14 Certainty of Evidence for KQ 1b

Outcome | Number of Studies(N) | Range of Effects | Certainty of Evidence(Rationale)
Adoption of targeted process of care activities
Composite process of care outcomes | 7 randomized trials; (381 practices and health service organizations) | 5 of 7 trials (83%; 95% CI 36% to 99%) with at least 1 outcome favoring the intervention; 4 trials with statistically significant findings | Low certainty that coaching probably has a beneficial effect on composite process of care outcomes (rated down for serious risk of bias and imprecision)
Organizational processes of care | 5 randomized trials (471 practices) | 4 of 5 trials (80%; 95% CI 28% to 99%) with at least 1 outcome favoring the intervention; 3 trials with statistically significant findings | Very low certainty that coaching possibly has a beneficial effect on organizational processes of care (rated down for serious risk of bias, inconsistency, indirectness and imprecision)
Appropriate documentation | 4 randomized trials^b^ (142 practices) | 3 of 4 trials(75%; 95% CI 19% to 99%) with at least 1 outcome favoring the intervention; 3 trials with statistically significant findings | Very low certainty that coaching possibly has a beneficial effect on appropriate documentation (rated down for very serious risk of bias and serious inconsistency)
Appropriate medication prescription | 4 randomized trials^b^; (140 practices) | 2 of 3 trials (66%; 95% CI 9% to 99%) with at least 1 outcome favoring the intervention; none statistically significant | Low certainty that coaching probably does not have a beneficial effect on appropriate medication prescription (rated down for serious risk of bias and serious imprecision)
Appropriate counseling | 2 randomized trials; (155 practices) | 2 of 2 trials (100%; 95% CI 16% to 100%); both statistically significant | Low certainty that coaching possibly has a beneficial effect on appropriate counseling (rated down for serious indirectness and imprecision)
Appropriate provider exams and procedures | 4 randomized trials; (255 practices) | 3 of 4trials(75%; 95% CI 19% to 99%) with at least 1 outcome favoring the intervention; 2 trials with statistically significant findings | Very low certainty of uncertain effect of coaching on improvement of provider exams/procedures (rated down for serious risk of bias, inconsistency, and imprecision)
Ordering of lab tests and vital signs | 5 randomized trials; (120 practices) | 5 of 5 trials (100%; 95% CI 45% to 100%); 4 trials with statistically significant findings | Very low certainty that coaching probably has a beneficial effect on ordering of labs/vitals (rated down for serious risk of bias, inconsistency, and very serious imprecision)
QI process goal attainment (eg, the number of QI projects reaching completion)
Mean # of QI projects initiated | 1 randomized trial; (49 practices) | 3.9 QI projects per practice (intervention) vs 2.6 (comparator); p<0.001 | Low certainty that coaching possibly has a beneficial effect on number of the projects initiated (rated down for serious inconsistency and imprecision)
% mean indicators at target | 1 randomized trial; (23 practices) | Not significant^a^ | Very low certainty that coaching has no effect on the number of indicators at target (rated down for serious risk of bias, inconsistency, and imprecision)
Improved team member knowledge
No trials addressed this outcome | – | – | –
Improved team member self-efficacy
No trials directly addressed this outcome | – | – | –

a Authors only reported not significant results for comparison of relevance

b Only 3 trials provided valid information on direction of effect.

Abbreviations: CI=confidence interval; QI=quality improvement

## KEY QUESTION 2 What are the identified barriers and facilitators that impact the uptake of transformational coaching in a large health care system such as the VA?

### Literature Flow for KQ 2

For the KQ 2 search, we identified 3,354 articles through searches of MEDLINE^®^ (via Ovid^®^), EMBASE, and CINAHL (Figure 7). When reviewing bibliographies of relevant review articles, no studies were identified. After removing duplicates, there were 1,867 articles. After applying inclusion and exclusion criteria to titles and abstracts, 172 articles remained for full-text review. Of these, 16 articles were retained for data abstraction. Four articles^19,59–61^ reported on 2 interventions that were included in KQ 1 as well.^49,52^ The 16 studies consisted of 10 qualitative studies, 3 mixed method studies, 2 multi-method studies, and 1 survey. Included studies were conducted in Canada, Denmark, Norway, and the USA.

Figure 7 Literature Flow Chart: KQ 2

### Key Points

- The interdependent nature of the components of the transformational coaching intervention—the intended role of the coach, the quality improvement (QI) project, and the context—requires that the coach see both the big picture context as well as the specific details of a given team and QI project to overcome barriers and maximize facilitators.
- Collaboration, goal setting, and expectation management for the QI project and coaching process is key to the success of coaching and the project.
- Uptake of coaching is more successful when teams have the knowledge, skills, engagement level, support, and resources to apply learned coaching strategies to successfully conduct their QI projects.
- Adaptability is an essential characteristic of coaching, as the coach may need to modify the approach and/or QI project to fit the context and needs of the team.
- The variable availability of data was identified as a significant barrier for teams, as the lack of data hindered the ability of the coach to support the team, generate reports, address challenges, and provide education related to the data and QI project.
- The ability of the coach to foster multiple types of relationships including those with the team, among team members, and between the team and external support is an important aspect of coaching.

### Characteristics of Included Studies

Sixteen studies were included that address the facilitators and barriers of transformational coaching. All studies meeting eligibility criteria used qualitative or mixed methods (including 1 survey with open-ended questions). Eight were conducted in the United States,^15,62–68^ 5 in Canada,^59,60,69–71^ and 3 in Europe.^19,61,72^ All but 2 were conducted within the context of primary care or family medicine practices, and those 2 studies were set in nursing homes and health departments.^15,72^ The study designs of the studies included qualitative methods, mixed methods, and multi-methods, as well as survey-based design. Labels for the transformational coach-like role included practice facilitator, external facilitator, coach, QI coach, QI advisor, and nurse facilitator. The clinical context of the included interventions was cardiovascular health, electronic health record (EHR) use, chronic disease management, and improvement of general QI capacity. Interventions varied in duration from 5 weeks to 6 years. Included articles did not consistently describe the number of individuals within a team, disciplines of individuals within that team, and roles of the interdisciplinary team members.

### Detailed Findings

In this section, we describe barriers and facilitators related to the uptake of transformational coaching. We organize our findings by the 5 socioecologically informed domains in the Consolidated Framework for Implementation Research (CFIR)^34^: (1) Context, (2) Intervention Characteristics, (3) Individual/Team Characteristics, (4) QI Project/Process, and (5) Patients. Within each domain, we organize findings by relevant CFIR constructs (Figure 8).

Figure 8 Adapted CFIR and Ecological Frameworks

### Context

We defined context as any level outside the team that is receiving transformational coaching (Table 15) and included organizational factors as well as larger systemic issues. For coaching interventions, we determined that context most closely aligns with the CFIR domains of Outer Setting and Inner Setting.^34^ Within these domains, we mapped our findings of barriers and facilitators to these CFIR constructs: Implementation Climate (Inner Setting), Culture (Inner Setting), Readiness for Implementation (Inner Setting), Cosmopolitanism (Outer Setting), and External Policies and Incentives (Outer Setting). Overall, 11 studies contributed to themes under these constructs.^19,59–66,71,72^

Table 15 Consolidated Framework for Implementation Research: Context

CFIR Construct | FACILITATORS (Activities that promoted coach-like role) | BARRIERS (Activities that impeded coach-like role)
Inner Setting
Implementation Climate | | Lack of practice engagement due to relative priority, tension for change
Culture | - Positive, open-minded practice culture; - Long-standing relationship; - Aligning approaches with existing practice culture | - Practice behavior; - External facilitators having limited control
Readiness for Implementation | - Provision of expertise, knowledge, tailored recommendation; - Protected resources such as sufficient time and staff | - Lack of credible evidence and understanding of the intervention; - Lack of resources such as time, monetary cost, data, and technological knowledge
Outer Setting
Cosmopolitanism | | Lack of network for information exchange
External Policies and Incentives | Government approach | External influences (eg, environmental factors, policy-related factors)

#### Implementation Climate (Inner Setting)

We identified 1 barrier and no facilitators for Implementation Climate. The overall barrier related to how capacity for change and shared receptivity of practices influenced the implementation of the coaching. One example of this barrier occurred when the QI project was a low priority for the practice due to the practice’s competing demands. Additionally, a common occurrence was when unanticipated events shifted the focus of the practice and led to a loss of momentum for the QI project.^60,63,65,66^ This barrier also extended to resistance at the leadership level.^63,66^ Making and sustaining change was difficult when practice leadership did not prioritize the implementation of QI effort lacked interest in the QI project, or did not see the need for change. Additionally, difficulties occurred when practices had a vague notion of what to expect, a limited understanding of the intervention, a lack of engagement, and a resistance to change.^19,60^ One study perceived costs associated with QI effort (eg, human capital, hardware, software) that led to difficulty in fostering a positive implementation climate.^65^

#### Culture (Inner Setting)

We identified 2 barriers and 3 facilitators associated with the norms and values of a given organization that had an impact on the coaching implementation. One barrier was related to practice behavior.^60,66^ For example, a practice that resists involving individuals external to the organization could be a barrier for coaches, who are often not part of the practice organization. Additionally, coaches external to the organization may have limited control over the way practices are organized (eg, teamwork, practice readiness, and leadership structure).^60^ Being a person external to an organization may exacerbate this barrier depending on the practice’s culture.

One facilitator related to the internal culture of a practice was a willingness to engage in a coaching effort.^63^ Internal cultural shifts around the importance of an intervention or QI project also served as a facilitator.^66^ For instance, 1 practice shared their experience, “There was not a lot of emphasis [on PCMH] before. We’ve had big cultural shifts, which was positive for us.”^66^ A second facilitator focused on relationships, whereby a longstanding relationship between the coach and practice leaders was deemed helpful for carrying out QI projects.^63^ A third facilitator focused on coaching style. Examples included aligning the coaches’ approach with the existing practice culture^60^ and, similarly, adapting the coaching style to reflect interactions with the participating staff.^72^

#### Readiness for Implementation (Inner Setting)

We identified 2 barriers and 2 facilitators related to the tangible and immediate indicators of an organizational commitment to implement coaching. One barrier related to data challenges included limited access to internal reporting functionality and queries^64^ and technological difficulties such as setting up the data module^61^ and working with the electronic health record (EHR).^65^ The other barrier included having limited understanding of the intervention^19^ and a lack of reliable high-quality evidence to support the intervention.^71^

The first facilitator was provision of expertise, knowledge, and tailored recommendations.^19,59,62,63^ Examples included expertise with the EHR and how hands-on support from facilitators was deemed helpful to the team members.^62,63^ One clinician stated, “The practice facilitator was very instrumental in setting up parameters for us in the EHR. Any time we had any questions, she was always ready to either come or to guide us in the path to follow.”^62^ Assistance in setting up data modules for the QI project and having coaching meetings that focused on the practice also fostered a faster implementation process.^19^ Practices learned about community resources available to patients through the coaches. The coach’s tailoring of suggestions relevant to patients served by the practice was useful.^59^ The second facilitator was protected resources.^19,63^ Having protected time for coaching visits^19^ and having a stable group of physicians and staff members on the team receiving coaching^63^ were deemed advantageous in implementing coaching.

#### Cosmopolitanism (Outer Setting)

We identified 1 barrier and no facilitators related to the lack of a network for information exchange. One example of the barrier included how small, independent practices with few staff members were functioning in isolation, and thus clinicians did not have the network of colleagues for information exchange and learning about QI.^62^ The other example of this barrier occurred when the coach and site are located in different time zones.^15^ While a timely response to team members’ questions, requests, and concerns was seen as helpful, the lack of a timely response impacted the ability of the coaching intervention to work as intended.

#### External Policies and Incentives (Outer Setting)

One barrier and 1 facilitator were related to this construct. The barrier related to an environmental factor was an unanticipated competing demand. For example, an H1N1 influenza outbreak was an example of an unforeseen event that shifted the focus of the practices, and eventually impacted the coaching process by reordering clinical priorities.^60^ One practice facilitator stated, “I think to a large extent, you have to wait. Very often, you can’t move forward until these other issues have resolved in some fashion, and you have to respect that.”^60^ Policy-related factors were discussed both as barriers and facilitators. Practices identified the lack of external policy (eg, payment reform) aligned with ongoing QI efforts and their commitment to improving care as a second barrier.^65^ On the other hand, government-distributed guidelines, when consistent with best practices identified by the QI project’s expert panel, were perceived as a facilitator.^71^

Bottom Line

The external factors as well as internal culture/climate were potential determinants of transformational coaching. The external factors became a barrier if an unforeseen event occurred and thus shifted the practices’ focus and priority but also served as a facilitator if a policy was aligned with ongoing QI efforts. One notable facilitator was aligning the coaches’ approaches with the existing practice culture and, similarly, adapting the coaching style to reflect interactions with the participating staff.

### Intervention Characteristics

We determined the transformational coaching intervention itself most closely aligned with the CFIR domain of Intervention Characteristics.^34^ Within that domain, we mapped the findings of barriers and facilitators to these CFIR constructs: Cost, Adaptability, Design Quality and Packaging, and Relative Advantage (Table 16). Overall, 16 studies contributed to themes under these constructs.^15,19,59–72^

Table 16 Consolidated Framework for Implementation Research: Intervention Characteristics

CFIR Construct | FACILITATORS (Activities that promoted coach-like role) | BARRIERS (Activities that impeded coach-like role)
Cost | Availability of training for the practice facilitators | High workload for the coach
Adaptability | - Doing whatever it takes to complete the QI project; - Characteristics and behaviors of the coach | Coach did not provide support or information the practice desired
Design Quality and Packaging | - How coach engaged in coach role during QI project; - Practice facilitator was a knowledgeable resource for practice during QI project | - Not enough time for coach to complete coach activities; - Lack of knowledge or comfort with QI process; - Lack of technical or clinical knowledge
Relative Advantage | Active engagement by practice | Lack of engagement by practice

#### Cost

We identified 1 barrier and 1 facilitator related to costs associated with investment and opportunity for the coach during the QI project. The identified barrier was a high workload for the coach.^63,64,70^ Examples included that the coach found it burdensome to engage in completing the designated QI activities at the same time as collecting data for the QI project,^63^ or not having the anticipated prerequisite data available for the QI project and needing to spend time and effort identifying solutions.^64^ For example, “the [coaches] used over a quarter of their work time on administrative work. They searched for specific knowledge and strategies to address the challenges faced by the primary health care teams, sorted out questions and answers through emails, analyzed the best practice guidelines, and documented team progress.”^70^ Other examples included that the workload and daily coaching routine changed day to day, and that the coach spent time doing administrative tasks that took away from the ability to complete duties, including the actual coaching work.^70^ The identified facilitator focused on the investment of training for the coaches.^68,70–72^ For example, the availability of initial and ongoing training helped the coach engage in the QI process and understand their role as a coach. Additionally, training facilitated the development of a network of other coaches that enabled the exchange of knowledge and support about engaging in QI and applying QI concepts.

#### Adaptability

One barrier and 2 facilitators describe how coaches tailored and refined their role during the QI project. Of note, it is unclear if these adaptations were in keeping with fidelity to the intervention or not. The barrier occurred when the coach did not provide the support or information the team desired.^19,61,66^ For example, the coach did not provide materials to help practices retain information between coaching visits,^19^ was not available to answer questions in between meetings,^15^ did not meet often enough with the practice,^15^ or was unfamiliar with the culture and/or historical context of the practice.^66^ Additionally, scheduling meetings was a challenge when the coach and practice were in different time zones.^15^

The first facilitator consisted of the coach “doing whatever it takes” to complete the QI project.^59,60,62–71^ Examples include when the coach was an extra set of hands for the practice to complete the QI project such as serving as a liaison for the practice with external entities (ie, EHR vendor), helping to identify problems, and running reports.^59,60,62–66,68–71^ An additional feature of “doing whatever it takes” includes the coach developing strategies to overcome challenges encountered while engaging in the QI project.^60,64,66,67,69,70^ For example, 1 study noted that, “without performance data, [coaches] worked on workflows and ‘pain points’ identified by practices. They found they could strengthen relationships with practices by working on practice needs … [Coaches] reported that they found this strategy particularly useful in cases where practices were reluctant to select a specific … measure to work on without first seeing their performance data.”^64^

The second facilitator focused on characteristics and behaviors of the coach.^15,19,59–61,65,67–70,72^ An example was how the coach collaborated with, and engaged, members of the practice by asking questions and helping individuals at the practice take charge.^61^ Another was when the coach had technical knowledge (eg, knew how to use the practice’s EHR), clinical knowledge (eg, was a physician or nurse), or QI process knowledge appropriate for their role in the project.^15,19,59–61,65,67–70,72^

#### Design Quality and Packaging

We identified 3 barriers and 2 facilitators related to how the coach was presented to the practices during the QI project. The first barrier was not having enough time allotted for the coach to complete the coaching activities.^19,70^ Examples include not enough time for discussion in meetings^19,70^ and when the coach needed more time to get to know the practice.^70^ The second barrier was when the coach lacked knowledge and comfort with the QI process and/or the coach’s role.^15,19,61,63,64,68,70^ These instances occurred when the coach lacked sufficient QI training prior to and during the coaching intervention,^61,64^ did not have the information needed to engage in the role and QI process,^61,64^ did not facilitate discussion,^19^ and conducted meetings that lacked structure and organization.^15,19^ Notable instances also occurred when the coach did not clarify the reason for the QI project at the practice,^19,61,68^ did not engage with practices to tailor support,^19,61,68^ did not provide clear roles and instructions for the practice during the QI project,^19^ or lacked confidence in being seen as a role model or trainer.^61,70^ The third barrier was when the coach did not have the technical or clinical knowledge to facilitate the completion of the QI project.^19,66^

The first facilitator was how the coach engaged in the role during the QI project.^59,60,63,66–70^ Examples include how the coach fostered an ongoing and longitudinal relationship with the practice^59,60,63,66–70^ and that the coach and practice were in close geographic proximity.^70^ The second facilitator was how the coach was a knowledgeable resource for the practice during the QI project.^15,19,59–71^ Examples include how the coach exchanged information and support^15,19,59–71^ and was knowledgeable and flexible in completing activities in the coaching role.^60,67,69,70^

#### Relative Advantage

We identified 1 barrier and 1 facilitator related to whether the coaching intervention was viewed unfavorably or favorably. The barrier was related to a lack of engagement in the QI project by the practice.^19,63,70,72^ Examples include when the QI intervention was not a priority for the practice,^19,63^ there were limited resources in the practice for the project,^70^ the coach had to push the practices along to make a change,^70^ and different personalities in the practice made leading meetings challenging.^72^ Another example of this barrier was when there was a reliance on a single practice champion who subsequently left the practice.^63^ One study noted that when the QI project was not a priority in a busy practice, the coach found it challenging to have a function or role.^70^

The facilitator focused on instances when the practice was engaged in the QI project.^19,59–61,63,65,66,68–70^ Notably, in these instances the coach’s presence and actions helped hold practices accountable to making a change.^19,59–61,65,66,68–70^ The meetings with the coach were protected times for the practice, which may have helped create structure for change,^19,65^ and meetings occurred in a convenient location (ie, the practice).^19^ One study noted that the involvement, support, and investment of the practice leaders helped the coach implement the QI project.^63^

Bottom Line

The characteristics and knowledge of the coach were potential determinants of coaching uptake. One notable barrier was when the transformational coach lacked knowledge and comfort with the QI process and/or the coach’s role. One notable facilitator was when the coach “did whatever it took” to complete the QI project—in these instances the coach served as a liaison, ran reports, and identified solutions to challenges the practice faced.

### Individual and Team Characteristics

We determined that the recipients of the transformational coaching intervention most closely aligned with the CFIR domain of Characteristics of Individuals.^34^ Within that domain, we mapped the findings for barriers and facilitators to these CFIR constructs: Knowledge and Beliefs about the Intervention, Individual Stage of Change, and Other Personal Attributes. Given the nature and definition of transformational coaching, we included the team as a unit receiving the coaching in addition to individuals on the team (Table 17). Overall, 12 studies contributed to themes under these constructs.^15,19,59,60,62–64,66–68,70,72^

Table 17 Consolidated Framework for Implementation Research: Individual and Team Characteristics

CFIR Construct | FACILITATORS (Activities that promoted coach-like role) | BARRIERS (Activities that impeded coach-like role)
Knowledge and Beliefs about Intervention/Process | Open attitude | - Lack of knowledge; - Lack of ability to work with data
Individual and Team Stages of Change/Process | - Tailoring; - Engagement; - Instrumental support | - Resistance to change; - Limited engagement
Other Personal Attributes | - Relationship with coach; - Leadership style; - Collaboration | - Poor team dynamics; - Competing priorities; - Team leadership challenges; - Team size

#### Knowledge and Beliefs About the Intervention and Process

The knowledge and attitudes of the individuals and teams being coached can impact the success of both the QI process and the coaching intervention. We identified 2 barriers and 1 facilitator for this construct. The first barrier occurred when the team’s ability to implement the QI project was impeded by a lack of knowledge or gap in understanding.^15,19,64,66^ Specifically, a lack of understanding was not knowing what to expect from the coach,^19^ a lack of familiarity with the QI projects being implemented,^15,66^ or limited knowledge of the technical aspects of the EHR.^64^ In addition, the team’s ability to work with the data aspect of a QI project posed challenges for the coach to overcome.^64^ One coach relayed such an experience with a team member, stating, “When we started this process, she [the provider] sat down and said, ‘I have no idea what we are even looking for.’ I walked her through the screens to the existing quality reports and we did not find what we needed. We decided to call technical support for the EHR. She said, ‘I do not even know what to ask for, can you please explain to them what we need?’ So I explained it to them as we sat together.”^64^ On the other hand, clinical team members who displayed a more “open attitude to improvement” tended to implement more impactful changes in practice.^59^

#### Individual and Team Stages of Change

The readiness or willingness to change on the part of the individual or team has implications for the ability of the coach to support the QI process. Two barriers and 3 facilitators aligned with this construct. First, the team’s resistance to change created a barrier.^60,64,66,68^ Some individuals within the teams did not feel the need to make changes due to perceived QI project implementation barriers,^64,68^ failures with prior QI attempts leading to a skeptical attitude that the current effort would have a different outcome,^66^ a lack of relevant training related to the systems change the practice was trying to implement,^66^ or displeasure with QI tools and coach feedback. For example, “They did not always welcome coaching feedback and frequently disliked the technical tools and collaborative processes.”^68^ In addition to resisting change, limited engagement with the QI process and/or coaching was identified as a second barrier.^19,60,66,70^ Some teams were described by the coach as having low levels of engagement, which posed an additional obstacle to overcome.^60,66^ Teams exhibited limited buy-in when they did not recognize the need for a change to occur.^19^ Teams with low engagement described that they would have experienced limited progress if it were not for the supportive efforts of the coach.^60,66,70^ Additionally, frustration with the technological aspects (eg, data access, EHR capabilities) of the project created barriers to both the coach and the QI process.^19^

The ability of the coach to tailor their approach to the teams’ characteristics was viewed as a facilitator.^19,60,63,64,72^ Coaches who used a flexible approach to meet the team’s needs were viewed as helpful to the team.^63,64^ The individualization of approach including offering choices,^19^ understanding and accounting for practice-specific settings,^19^ and choosing strategies to help the team and individuals on the team.^60,63,72^ For example, a coach said the following, “I was able to present to the team the option of looking at the clinical improvement side while we wait for the data IT issue to be resolved. This brought forth great brainstorming and excitement from the team.”^64^ The second facilitator was engagement of the team which positively impacted the coaching and QI processes.^60,63^ The team’s commitment was influenced by having a consistent group of individuals with no turnover engaging in the QI project,^63^ the presence and active participation of a practice champion,^60^ and the team’s open-minded culture.^60,63^ The team also had an easier time engaging when they were familiar with the EHR^63^ and had a consistently involved coach.^60^ In addition, the teams felt they were better equipped to make changes when they had institutional support, which allowed the teams meet the desired outcome.^19,62–64,66,70^ For example, the specific tools the coach provided to help with the change process included education,^19,63,66^ helping the teams with goal-setting needs,^19,63,70^ and developing the team’s EHR skills.^62,64^

#### Other Personal Attributes

Selected characteristics of the team and individual members can influence the coach’s ability to facilitate QI implementation. There were 4 barriers and 3 facilitators for this construct. The first barrier was poor team dynamics or negative interactions among the team members.^60,67,70^ For example, when team members experienced conflict with one another,^60,67^ or lack of comfort with each other,^70^ the negative aspects of the relationship posed a barrier to coaching and QI implementation. Organizational structure, such as a hierarchy, could also hinder implementation of QI.^60^ Second, when teams faced competing demands, it was difficult for the team to participate in QI activities or complete the QI project.^19,60,63^ Some clinical teams faced limited time available to devote to QI,^60,63^ and the coach found it difficult to schedule time with the each team.^60^ When meetings or QI did get scheduled, the team did not always have an opportunity to focus on the QI process or interact fully with the coach due to general interruptions^19^ and urgent clinical issues.^60^ A third barrier arose for some teams when practice leaders posed an obstacle for the coach to overcome.^63,66,68,72^ In some instances, practice leaders controlled the decisions such as how often the coach could meet with the team^63,66^ or what staff might be involved and what projects could be implemented rather than collaboratively making decisions with the team and/or the coach. The coach also described the negative impact of difficult relationships with leaders.^68^ The level of engagement and/or resistance of the leader helped set the tone for the team. When the leader was not engaged,^72^ the team may not have been as supportive of the process^66^ or efforts may have stalled.^72^ A fourth barrier was noted by 1 study which noted that teams comprised of fewer individuals seemed to appreciate the coaching services more.^62^

The first facilitator was that the team’s positive relationship with the coach was viewed as helpful.^60,66,68^ Specifically, the team appreciated an ongoing relationship with the coach^66^ as well as the encouragement and feelings of support the coach provided to them.^68^ Other teams appreciated the coach’s efforts to integrate into the team^60^ so they had a better understanding of the team’s dynamics. Some teams also welcomed the feedback that an external coach was able to provide.^66^ While leadership style can be a barrier if obstructive, it may also be a facilitator if participatory.^60,66,68,72^ For example, practice leader actions were facilitators for coaching when they engaged with the QI process,^60,72^ gained increased confidence during the process,^68^ and created a supportive culture.^66,72^ One coach noted that when facilitating change for bigger teams, it is essential to have the leaders on board: “For that kind of change, you would need the clinical lead …. You see, individual people might sign up, but the head of that team might not. And you really need buy-in at the highest level to do anything.”^60^ Improved collaboration among the team was facilitated by new communication skills, team problem- solving, and redefined responsibilities.^67^

Bottom Line

The team’s knowledge, skills and attitudes were all potential determinants of transformational coaching. The need for knowledge and skills related to obtaining and using data were particularly important. The team’s attitude toward the change contributed to their level of engagement. One facilitator of note was the coaches’ ability to meet the team’s needs through a tailored approach.

### Quality Improvement Project/Process

We considered the actual QI project that an interdisciplinary team was being coached on as its own construct and that it most closely aligned with the Process domain in the CFIR framework.^34^ We mapped the findings by barrier and facilitator under these CFIR constructs: Planning, Executing, and Reflecting and Evaluating (Table 18). Overall, 12 studies contributed to themes under these constructs.^15,19,59,61,63–67,70–72^

Table 18 Consolidated Framework for Implementation Research: QI Project/Process

CFIR Construct | FACILITATORS (Activities that promoted coach-like role) | BARRIERS (Activities that impeded coach-like role)
Planning | - Fit of QI Project; - High-quality project materials and resources | - Mismatch of project and team members; - Unclear roles and tasks; - Poor QI design; - QI project timelines
Executing | - Application of coach QI techniques knowledge and skills; - Application of coach technology/data knowledge and skills; - Workarounds for data systems | - Mismatch of project demands; - Inability to collect QI data; - Not following intended QI project processes
Reflecting and Evaluating | | Data obstacles

#### Planning

We identified 4 barriers and 2 facilitators for this construct. Barriers related to a mismatch of project and team priorities; unclear roles and tasks; poor QI design; and inappropriate QI project timelines. The first barrier arose when a team’s preferred interaction style or clinical priorities were not aligned with the focus and conduct of a given QI project^61,63^; for example, “both practice leaders and [coaches] said that the program was focused on improving patient care and documentation, but not patient adherence to treatment, which was a more immediate and vexing problem.”^63^ A second barrier occurred when poorly designed QI projects and processes impeded project success. This occurred when the structure of a QI project (eg, inconvenient meeting times or lack of responsibility designations) did not support the desired team QI milestones or planned processes (eg, reflective discussions or leadership follow-through).^61,72^ Another example included physical obstacles to implementing a QI project as planned, such as when a clinic was unable to rearrange their waiting room to meet isolation precautions during flu season as dictated by their preplanned QI project.^71^

A third barrier arose from unclear project roles and tasks for either the team generally or their leadership in particular. Lack of clarity or guidance around steps in between coaching sessions led to failure of teams carrying project activities forward.^61,72^ Teams often stated a desire for the coach to be more present and involved in local QI activities to boost momentum, particularly when teams were busy.^70^ A fourth barrier was inappropriate QI project timelines. Multiple studies noted that there was no single right timeline for a particular QI project that would be appropriate across all teams or practices. Rather, timelines needed to be tailored to a particular team’s availability and skillset.^15,67,70,71^

Facilitators for planning QI projects focused on a good fit for a given team and clinical practice setting and high-quality materials and resources. The first facilitator was appropriate QI outcome measures and strategies that supported engagement with the project and energized the teams.^61,63,65,66,71^ One way that coaches supported the right fit was by having teams articulate their thoughts and ideas about the planned QI activities.^61^ Project challenges offered an opportunity for adaptations or adjustment to planned activities that could further improve project fit.^63^ A second facilitator was offering teams high-quality project materials and resources.^63^

#### Executing

We identified 3 barriers and 3 facilitators for this construct. The first barrier was a mismatch between the QI project and resources that manifested in 2 ways. One way was when the project requirements were not a good fit for the coach’s skills (eg, a lack of familiarity with the team’s electronic health record).^61^ A second way was when the team was not able to collect the QI data required for project activities.^19,63^ If teams were unable to extract needed data or reports from their EHR—either due to lack of knowledge or technical limitations—projects could stagnate and team engagement could suffer: “[T]he technical problems experienced in the process triggered increased frustration with the [EHR]: ‘Well it is just difficult to mobilize any energy among the doctors.’”^19^ It was also problematic during project execution when teams and coaches did not engage in planned activities, particularly internal reflection and discussion.^61^

The most widely reported facilitator for this construct was the direct sharing of QI technique, knowledge, and skills by the team’s coach.^15,59,61,64,66,67^ Multiple specific QI techniques were mentioned including chart audits, daily team huddles, and creating cause and effect diagrams. Other particular actions by the coach that were found to be helpful during the course of engaging in QI project activities included having the coach connect teams to community resources^59,64^ and having coaches share their own experiences conducting similar QI projects.^61^ Similarly, when coaches were able to provide technical support either at a general level or one-on-one, this was found to be valuable to teams and often offered “quick wins.”^19,61,63,64^ Technological support for coaches facilitated intervention activities when teams were able to find data workarounds for roadblocks, allowing the project to move forward.^64^

#### Reflecting and Evaluating

There was only a single barrier for this construct, having to do with problems with acquiring needed data during the execution of QI project activities, acquiring data necessary for project evaluation was problematic in many cases.^61,63^ We identified no facilitators for reflecting and evaluating.

Bottom Line

QI project purpose, design, and data requirements were all potential determinants of transformational coaching uptake. The fit of these QI project characteristics to the interest and skills of the team conducting the QI project and the skill set of the coach supporting that team could be both a barrier (if a poor fit) or a facilitator (if the fit was good). One notable facilitator at the QI project level was when coaches taught specific QI strategies and techniques for teams to apply during project conduct.

### Patients

While we identified the patient as a separate level in our socioecologically informed CFIR domains, we did not identify any barriers and facilitators at this level.

### Quality of Evidence for Key Question 2

For the 16 qualitative studies included in KQ 2, ROB concerns were found under appropriateness of methodology (n=1),^15^ match between recruitment strategy and study aims (n=1),^72^ data collection (n=2),^68,72^ consideration of relationship between researcher and participant (n=2),^71,72^ analytic rigor (n=3),^15,71,72^ and lack of clarity of research findings (n=1).^72^ There was frequently insufficient information for assessment of relationship between researcher and participant and consideration of ethical issues. Risk of bias ratings for each study are shown in Figure 9, and the ROB ratings across all studies are shown in Figure 10.

Figure 9 Risk of Bias for Included Studies in KQ 2

Figure 10 Risk of Bias Assessment Across Included Studies (n=16) in KQ 2

### Certainty of Evidence for Key Question 2

The overall confidence of the evidence was assessed using CERQual for the findings within each of the 5 CFIR constructs prioritized by our operational partners is shown in Table 19. A detailed table is in Appendix F.

Table 19 CERQual Summary of Qualitative Findings Table for KQ 2

Summary of Review Findings | Studies Contributing Review Finding | CERQual Assessment of Confidence in the Evidence | Explanation of CERQual Assessment
External policy and incentives (context: inner and outer setting)
Barriers:; External policy not aligned with the ongoing QI effort; When the external policies governing practice level activities were not consistent with requirements of a QI project, this was problematic. For example, practices expressed the need for payment reform to align with the ongoing time and effort they are committing to improving quality of care. | Fernald, 2014^65^ | Very low confidence | This finding was graded as very low confidence because of significant concerns regarding methodological limitations and significant concerns regarding adequacy.
Barriers:; Unanticipated competing demands shift focus on QI; When teams were faced with unexpected events from outside the practice, their focus on coaching and QI could be derailed. For example, practices working on QI activities during the H1N1 influenza outbreak found it difficult to retain momentum. | Liddy, 2014^60^ | Low confidence | This finding was graded as low confidence because of significant concerns about adequacy moderate concerns regarding methodological limitations.
Facilitators:; Project alignment with Government guidelines; Coaching was more successful when QI project activities were aligned with guideline-identified best practices. For instance, the Ministry of Health distributed guidelines for respiratory infection control in community settings which were consistent with the QI intervention to improve respiratory infection control. | Huston, 2006^71^ | Low confidence | This finding was graded as low confidence because of significant methodological limitations and concerns about adequacy.
Relative advantage (transformational coaching/intervention characteristics)
Barriers:; Lack of engagement by practice; When practices were not invested in activities related to their QI projects or transformational coach, it was difficult for coaches to deliver the intended QI project. Examples of lack of engagement included when teams did not prioritize the planned QI intervention and when practices had limited resources allotted for transformational coaching and QI activities. Coaches found that when lack of engagement occurred, they had to “push” practices along and, at times, had difficulty finding a role for themselves within a busy practice. | McHugh, 2018^63^ Due, 2018^19^Kotecha, 2015^70^Mekki, 2017^72^ | Moderate confidence | This finding was graded as moderate confidence because of minor concerns regarding methodological limitations and moderate concerns about adequacy.
Facilitators:; Active engagement by practice; Examples of practice engagement included teams having protected time and a convenient location for coaching activities, and the support of practice leadership. When engaged, coach presence and the coach’s actions helped practices be accountable during the QI project to making a change. | McHugh, 2018^63^ Due, 2018^19^ Due, 2017^61^ Fernald, 2014^65^ Buscaj, 2016^66^ Lassard, 2016^69^ Liddy, 2016^59^ Kotecha, 2015^70^ Liddy, 2014^60^ Godfrey, 2014^68^ | Moderate to high confidence | This finding was graded as moderate to high confidence because of moderate concerns regarding methodological limitations.
Cost (intervention characteristics/transformational coaching)
Barriers:; High workload for coach; Coaches found it burdensome when, in addition to their planned QI support role, they had to compensate for data problems such as needing to collect data directly. Other sources of additional workload came from administrative tasks and a constantly changing daily routine. | McHugh, 2018^63^ Hemler, 2018^64^ Kotecha, 2015^70^ | Moderate confidence | This finding was graded as moderate confidence because of minor concerns regarding methodological limitations and moderate concerns about adequacy.
Facilitators:; Investing in training coaches; It was beneficial when coaches had adequate initial and ongoing training to help them with the QI process and understanding their role as a coach. One way to support ongoing training for coaches was the creation of a network of other coaches to learn from during coaching activities. | Kotecha, 2015^70^ Godfrey, 2014^68^ Mekki, 2017^72^ Huston, 2006^71^ | Low confidence | This finding was graded as low confidence because of significant concerns regarding methodological limitations and moderate concerns about adequacy.
Knowledge and beliefs about the intervention (individual or team characteristics)
Barriers:; Lack of knowledge; Team level lack of knowledge regarding the coaching process, QI project details, and technical aspects of electronic medical records as they relate to QI data collection was a barrier to coaching success. | Hemler, 2018^64^ Due, 2018^19^ Buscaj, 2016^66^ McKeever, 2014^15^ | Low confidence | This finding was graded as low confidence because of significant concerns regarding methodological limitations and moderate concerns regarding adequacy.
Barriers:; Lack of ability to work with data; Coaches experienced challenges when teams were not comfortable or readily able to work with QI data. | Hemler, 2018^64^ | Very low confidence | This finding was graded as very low confidence because of significant concerns regarding adequacy and moderate concerns regarding methodological limitations.
Reflecting and evaluating (QI project)
Barriers:; Data obstacles; Teams often had trouble acquiring the needed data for a given QI project which interfered with evaluating projects as planned. This led to team frustration and an inability of the coaches to execute relevant coaching implementation activities. | McHugh, 2018^63^ Due, 2017^61^ | Moderate confidence | This finding was graded as moderate confidence because of minor concerns regarding methodological limitations and moderate concerns about adequacy.