# METHODS

We followed a standard protocol for this review developed in collaboration with operational partners and a technical expert panel. The PROSPERO registration number is CRD42020165069. The protocol was developed prior to the conduct of the review, and there were not significant deviations after registration. Each step was pilot-tested to train and calibrate study investigators. We adhered to the Preferred Reporting Items for Systematic Reviews and Meta Analyses (PRISMA) guidelines.^20^

## TOPIC DEVELOPMENT

This topic was requested by the leadership of the National Transformational Coach Captain (NTCC) Program managed by the VHA Office of Veteran Access to Care. Findings from this report will be relevant to the VHA as it seeks to continue the provision of high-quality clinical care to the Veteran population. The results of this project may also be relevant to health care organizations and practices that seek to improve the efficiency and impact of their QI efforts.

### Definition and Conceptual Model

Transformational coaching is not explicitly defined or studied in the wider literature. Thus, for this review we needed to identify those interventions in peer-reviewed publications that shared the essential ingredients of transformational coaching such that would support comparison. So we worked with our operational partner to establish a contextually-relevant definition of transformational coaching through a series of communications and iterative revisions. We adapted our definition from a definition of health coaching by Wolever and colleagues.^21^ Specifically, through a series of communications with our operational partner, we elicited both the required and optional conditions by which an intervention would qualify as transformational coaching based on the underlying goal of such an intervention and the core activities of the coach-like role. From these factors, we developed a preliminary definition which was iteratively refined with input from our partners. The final definition for transformational coaching is as follows:

Transformational coaching is a team-centered approach wherein an external, clinical content-agnostic individual (ie, the coach) supports an interdisciplinary health care delivery team within the context of a longitudinal, proactive relationship in pursuit of catalyzing and/or building capacity for sustained change and improvement processes through providing support such as assisting with goal setting, goal attainment, connection to system level resources for change, and/or improving efficiency and team dynamics around change/improvement processes.

For clarity, “external” is used in this definition to mean that the coach is an individual who is not part of the interdisciplinary health care team or unit that is receiving the coaching. However, the coach could be from the larger health care system in which a given team or practice belongs.

We developed a conceptual model to clarify the relationship between the key questions for this report and the larger context of transformational coaching for health care teams working on improving the quality of their delivery of patient care (Figure 1).

Figure 1 Transformational Coaching Conceptual Model

Interdisciplinary health care delivery teams are embedded within larger health systems and work together to change and improve the quality of the care they deliver. As shown in Figure 1, transformational coaching is an intervention that is applied over time through multiple contacts to the health care team (or practice) as the team works on QI projects. The actual QI project that a given team is working on, and which the coach is supporting, could include such activities as increasing adherence to guideline-concordant care recommendations, improving organizational practices, adopting new models of care, or generally increasing team knowledge and use of QI skills.

The effect of transformational coaching can be measured at multiple levels, including at the level of care delivery actions by the health care team (ie, process outcomes) or the level of patient outcomes (ie, clinical outcomes). In KQ 1a, we mapped all outcomes included in studies that evaluated the effectiveness of transformational coaching at the levels of practice, provider, and patient. In KQ 1b, we examined the effects of transformational coaching on selected process of care outcomes such as provider or health care team actions/behaviors during the course of delivering clinical care (eg, ordering of guideline-concordant medications for a given disease or obtaining physical exam measurements at recommended intervals). In KQ 2, we focus on the determinants (ie, barriers and facilitators) to the uptake of transformational coaching for support of QI efforts of a given health care delivery team. We use the term “uptake” to mean the early-to-mid-implementation stage activity of adoption or intention to try a treatment or program by providers or organizations.^22^

## SEARCH STRATEGY

We collaborated with an expert reference librarian to conduct 2 primary literature searches—a search for KQ 1 and a different search for KQ 2. We searched MEDLINE^®^ (via Ovid^®^), Embase (via Elsevier), and CINAHL Complete (via EBSCO) from inception through October 7, 2019. We found no MeSH term matching the concept of transformational coaching, so we identified additional free-text terms (eg, practice facilitator, change agent, QI coach) to search titles and abstracts (Appendix A). Based on existing systematic reviews and with input from our operational partners and technical expert panel (TEP), we identified the most commonly used terms and pseudonyms for a person (or persons) who potentially shared the essential ingredients based on our operationalized definition of transformational coaching above. We conducted hand-searches of references from selected high-quality systematic reviews and exemplar studies identified during the topic development process and by our stakeholders and/or technical expert panel. Search terms identified (ie, improvement advisor, improvement coach) after execution of the literature search were searched independently, and any relevant references were imported into 2 electronic databases (for referencing, EndNote^®^, Clarivate Analytics, Philadelphia, PA; for data abstraction, DistillerSR; Evidence Partners Inc., Manotick, ON, Canada). Our search strategy for KQ 1 was informed by the Cochrane Effective Practice and Organisation of Care (EPOC) Group.^23^ EPOC criteria were developed to capture both randomized and nonrandomized study designs. We adopted a separate series of terms specific to the qualitative literature for KQ 2.

## STUDY SELECTION

Studies identified through our primary search were classified independently by 2 investigators for relevance to the KQs based on title and abstract based on our a priori established eligibility criteria. All citations classified for inclusion by at least 1 investigator were reviewed at the full-text review level. The citations designated for exclusion by 1 investigator at the title and abstract level underwent screening by a second investigator. If both investigators agreed on exclusion, the study was excluded. All articles meeting eligibility criteria were included for data abstraction. The outcomes used to assess transformational coaching (KQ 1a) were drawn from included publications identified in the KQ 1b search.

Tables 2 and 3 describe the eligibility criteria for this review. We used PICOTS (population, intervention, comparator, outcome, timing, setting) format for KQ 1,^24^ and SPIDER (sample, phenomenon of interest, design, evaluation, research type) format for KQ 2.^25^ Eligibility criteria also include detailed criteria for eligible study designs and limitations related to language, countries, and publication type.

Table 2 Study Eligibility Criteria for KQ 1

Study Characteristic | Inclusion Criteria | Exclusion Criteria
Population | Established interdisciplinary health care delivery teams (including clinic- or unit-level) | - Individual-level coaching; - Coaching with teams, not providing direct patient care; - Mixed populations of individual and team participants if <50% are team based; - Single profession teams
Interventions | Must have these 3 transformational coaching features:; 1. Clinical content-agnostic (not required to be an expert in the specific clinical topic or intervention that is the focus of the QI project); 2. Coach is external to the target of coaching (ie, not a member of the health care delivery team being coached); 3. Aims to catalyze and/or build capacity for sustained change and improvement through activities such as assisting with goal setting, goal attainment, connection to system-level resources for change, and/or improving efficiency and team dynamics around change/improvement processes | - Interventions that do not include all 3 features; - Interventions for which the effect of transformational coaching cannot be isolated; - Interventions that focus on learning collaborative as the main component of the intervention or have a longitudinal learning collaborative component delivered with coaching; - Interventions that are focused on generic team dynamics not necessarily around a QI project or QI capacity
Comparators | Any comparator (eg, usual care, active comparator) | None
Outcomes | Must have at least 1 of these 4 outcomes:; 1. Adoption of targeted process of care activities (ie, increased appropriateness of documentation of screening); 2. QI process goal attainment (ie, number of QI projects reaching completion); 3. Team member knowledge (defined broadly as the body of information relevant to a specific QI project topic, practice, or general QI skill); 4. Team member self-efficacy (defined as a team member’s belief in their capacity to execute a specific behavior targeted by a given QI project, or specific QI behaviors that could be applied in a clinical setting) | Not applicable
Timing | More than 1 coaching interaction | Not applicable
Setting | Any health care system setting | Exclude non-health care settings such as offices within a health care system that do not deliver patient care, business settings, etc.
Study designs^a^ | EPOC study designs:; - Randomized trials; - Nonrandomized trials; - Controlled before-after studies; - Interrupted time series; Study design must allow for the assessment of the isolated effect of a transformational coaching-like intervention (ie, co-administered interventions such as learning collaboratives were only allowed if occurred 1 time or were minor components of the intervention) | - Non-EPOC study designs (eg, cohort studies, case-control, cross-sectional, case reports); - Self-described pilot studies and/or sample size <0; - Studies with retrospective data collection; - Systematic reviews or meta-analyses
Language | Any
Countries | OECD^b^ | Non-OECD
Years | Any | Not applicable
Publication Types | Full publication in a peer-reviewed journal | Letters, editorials, reviews, dissertations, meeting abstracts, protocols without results

a See Cochrane EPOC criteria for definitions and details.

b OECD = Organization for Economic Co-operation and Development includes Australia, Austria, Belgium, Canada, Chile, Czech Republic, Denmark, Estonia, Finland, France, Germany, Greece, Hungary, Iceland, Ireland, Israel, Italy, Japan, Korea, Latvia, Luxembourg, Mexico, Netherlands, New Zealand, Norway, Poland, Portugal, Slovak Republic, Slovenia, Spain, Sweden, Switzerland, Turkey, United Kingdom, United States. Abbreviations: EPOC=Effective Practice and Organisation of Care; NCOD=National Center for Organization Development; QI=quality improvement

In addition to interventions that isolate the effect of transformational coaching roles, for KQ 2 we allowed inclusion of those studies in which the transformational coaching approach was delivered with a co-intervention such as longitudinal coaching so long as the primary purpose of the study was to explore barriers and facilitators of the coach-like role specifically.

Table 3 Study Eligibility Criteria for KQ 2

Study Characteristic | Inclusion Criteria | Exclusion Criteria
Sample | Any member of an interdisciplinary health care delivery team that receives transformational coaching (including clinic- or unit-level) | - Recipients of individual-level coaching; - Members of interventions delivered to mixed populations of individual and team participants if less than 50% are team-based
Phenomenon of Interest | Must have these 3 transformational coaching features:; 1 Clinical content-agnostic (not required to be an expert in the specific clinical topic or intervention that is the focus of QI project); 2 Coach is external to target of coaching (ie, not a member of health care delivery team being coached); 3 Aims to catalyze and/or build capacity for sustained change and improvement through activities such as assisting with goal setting, goal attainment, connection to system-level resources for change, and/or improving efficiency and team dynamics around change/improvement processes | - Interventions that do not include all 3 features
Design | Interviews (individual, dyad, group; semi-structured or structured), focus groups, observations, surveys
Evaluation | Primary purpose is to evaluate determinants of uptake of transformational coaching by a health care delivery team | Evaluations of determinants of uptake of a specific clinical intervention or QI project that is the focus of transformational coaching
Research Type | Case studies, qualitative, survey, mixed or multiple methods
Countries | OECD^a^ | Non-OECD

a OECD = Organization for Economic Co-operation and Development includes Australia, Austria, Belgium, Canada, Chile, Czech Republic, Denmark, Estonia, Finland, France, Germany, Greece, Hungary, Iceland, Ireland, Israel, Italy, Japan, Korea, Latvia, Luxembourg, Mexico, Netherlands, New Zealand, Norway, Poland, Portugal, Slovak Republic, Slovenia, Spain, Sweden, Switzerland, Turkey, United Kingdom, United States.

## DATA ABSTRACTION

For KQ 1a and KQ 1b, data from published reports were abstracted into a customized DistillerSR database by 1 reviewer and over-read by a second reviewer. Disagreements were resolved by consensus or by obtaining a third reviewer’s opinion when consensus was not reached. Data elements include descriptors to assess applicability, quality elements, intervention details, and all measured outcomes. Multiple reports from a single study were treated as a single data point, prioritizing results based on the most complete and appropriately analyzed data. Key features relevant to applicability included the match between the sample and target populations (eg, age, large health care system).

For KQ 2, we abstracted key study characteristics into a customized DistillerSR database by 1 reviewer and verified by a second reviewer. These characteristics included intervention characteristics (eg, coach training and discipline, delivery modality, key intervention components), setting (eg, primary care, emergency room), method of data collection (eg, focus groups, individual interviews), and source of data (eg, coaches, teams receiving coaching). Barriers and facilitators (ie, descriptions of elements that foster or impede the uptake of coaching) were abstracted directly into NVivo, a specialized software suited for textual data gathering and synthesis.

For details of study characteristics, see Appendix B. For details of implementation strategies, see Appendix C. Appendix D lists excluded studies and the reason for exclusion.

## QUALITY ASSESSMENT

For both KQ 1 and KQ 2, quality assessment was done by 2 investigators, and discrepant findings were resolved via discussion or, when needed, by arbitration with a third investigator.

For KQ 1, we used the Cochrane EPOC risk of bias (ROB) tool.^23^ These criteria are adequacy of randomization and allocation concealment; comparability of groups at baseline; blinding; completeness of follow-up and differential loss to follow-up; whether incomplete data were addressed appropriately; validity of outcome measures; protection against contamination; selective outcomes reporting; and conflict of interest. We assigned a summary ROB score (low, moderate, or high) to individual studies.

For KQ 2 qualitative studies, we used the Critical Appraisal Skills Programme (CASP) tool.^26^ These criteria address the appropriateness of the qualitative approach using the following broad areas of assessment: validity of study results (clarity of aims, appropriate methodology/design/data collection), nature of the results (ethical consideration, rigorous data analysis, clarity of findings), and how helpful the results will be (local value). There is no summary ROB score for this measure at the individual study level. For mixed/multiple methods studies for which we only considered the qualitative portion, we applied the CASP tool to the portion of the study included.

## DATA SYNTHESIS

Note that for clarity during the rest of the report, we refer to transformational coaching and coaching for all studies meeting our eligibility criteria even if the primary study used a different term or label for the intervention or interventionist (eg, practice facilitator, outreach visitor). In our study characteristics tables (Appendix B), we include the term used by the primary study authors for the intervention/interventionist. In Table 4, we show the various terms for the coach-like role across studies included for each KQ. In addition, we refer to the transformational coach, or simply coach, as the individual (or role sometimes filled by multiple individuals) delivering the intervention components, and transformational coaching or coaching intervention as the overall intervention in which multiple strategies are used to support interdisciplinary teams in the conduct of QI activities.

Table 4 Terms Used for Transformational Coach-like Role in Included Studies by Key Question

KQ 1a, KQ 1b | KQ 2
Practice facilitator | Practice facilitator
Outreach facilitator | Peer facilitator
Technical assistant | Quality improvement advisor
Nurse facilitator | Quality improvement coach
Outreach visitor | Coach
Outreach visitor | External facilitator
Outreach visitor | Nurse facilitator

### KQ 1a

We collected all outcomes reported by studies meeting eligibility criteria for KQ 1b and organized them by the level at which they produced potential changes.^2^ Specifically, we grouped them by 2 types of process outcomes: either practice-level outcomes (eg, improved capacity of practice to transform care, creation of information systems for population) or provider-level outcomes (eg, use of point-of-care decision support for target condition/patients, prescription of guideline concordant medications). Other measures targeted clinical outcomes at the patient level (eg, improved individual health outcomes, improved patient experiences).

### KQ 1b

We summarized the primary literature using relevant data abstracted from the eligible studies. Summary tables describe the key study characteristics of the primary studies, which include study design, health care team composition and setting, intervention characteristics (eg, number of interactions, modality of interactions), interventionist characteristics (eg, discipline, training), and details of the comparator. Across each included study, we identified the intervention activities employed by coaches to support interdisciplinary teams and matched them to established implementation strategies based on Expert Recommendations for Implementing Change (ERIC).^27^ Of note, we considered several implementation strategy taxonomies (eg, Michie’s behavioral wheel,^28^ ERIC, and others) for this step. Ultimately, we selected ERIC because it is widely cited, incorporates relevant QI ideas, and because there is a Consolidated Framework for Implementation Research (CFIR)-ERIC matching tool^29^ supporting connection to the conceptual framework used in KQ 2. We identified outcomes across the included studies that fit into the KQ-specified outcomes of adoption of process of care activities, QI process goal attainment, team self-efficacy, and team knowledge. For adoption of process of care activities, we grouped outcomes by the complexity of the actions required to enact. For example, process outcomes that required a simple action on the part of the provider (ie, ordering a lab) were grouped together, while those requiring more complex interactions (ie, behavioral counseling with the patient) were grouped separately. We also grouped the multicomponent outcomes into a separate group (ie, completing a collection of patient care steps for those with diabetes). Next, we grouped outcomes by ROB status and similar intervention duration when possible (eg, 6 months, 12 months, or more).

Due to heterogeneity of outcome type (eg, pre-post percentages of achieving a process of care target vs a discrete scale of process of care adherence), outcome measure (eg, optimized prevention care measured as correctly administered processes of care minus inappropriate care delivery vs delivery of a specific prevention activity), and intervention duration, we determined that conducting a quantitative synthesis (ie, meta-analysis) to estimate summary effects was not appropriate. Instead, we employed a vote-counting method based on direction of effect.^30,31^ In this approach, the null hypothesis is that there is no relationship between the specific intervention and the outcome; thus we would expect there to be equal amounts of harmful/no effect and beneficial findings (50:50) across the studies. For each relevant outcome within a given subgroup, we categorized the intervention effect as harmful/no effect or beneficial based on the direction of effect without consideration for the magnitude or statistical significance. Data from studies were omitted from this analysis when there was insufficient information to determine the direction of effect. We calculated the proportion of beneficial findings, obtained the exact 95% confidence interval (CI) for the true proportion of beneficial findings, and employed an exact binomial probability test with 2-sided alpha to provide the p value (the probability of observing this or more extreme proportion if in fact the intervention was truly ineffective [ie, the proportion of beneficial studies is truly 0.5]). Exact CIs and p values were calculated using “binom.test” function in the R statistical package version 3.5.3 (R Foundation; https://www.R-project.org/). When a given study included multiple outcomes with different directions of effect, we conducted sensitivity analysis to explore impact on proportions if a given study were considered to be beneficial or harmful. The vote-counting approach avoids the error of ignoring potentially clinically significant results from underpowered studies; however, it does not take into consideration the magnitude or precision of effects. In addition, we analyzed the data narratively, focusing on documenting and identifying patterns of the effectiveness of transformational coaching across settings and outcome types. We analyzed potential reasons for inconsistency in treatment effects across studies by evaluating differences in the study population, intervention, comparator, and outcome definitions. For all analyses, we focused on studies at low or moderate ROB.

### KQ 2

Similar to the approach for KQ 1b, we summarized the primary literature meeting eligibility criteria for KQ 2 using relevant abstracted data. Summary tables describe the key study characteristics of the primary studies. We used a modified “best-fit framework” synthesis approach for the synthesis of findings in KQ 2, which offers a “pragmatic, flexible approach to integrating theory with findings from practice”^32^ and has been promoted as a means to synthesize findings across improvement studies. In the best-fit approach, investigators identify an existing published model that offers a “good enough” starting point from which to form the conceptual underpinning of the approach to analyzing abstracted textual data.^32^ Specifically, a priori themes are derived from the selected framework(s) and are used to code the data from included studies. Any data that cannot be coded against the identified framework requires the creation of new themes.^33^ Published frameworks can be identified through a separate purposive search or opportunistically via topic-relevant searches.^32,33^

Given our timeline and team capacity, we reviewed and considered commonly used frameworks in VA implementation studies. We ultimately chose to use the Consolidated Framework for Implementation Research (CFIR)^34^ because it was developed for, and has been used widely within, the VA to assess implementation of complex interventions, and because at the time of selecting a framework, we were uncertain about the variety of concepts we would identify in the literature and felt that the breadth of CFIR’s included constructs would accommodate our analysis needs. Early in this process, we found the need to adjust our best-fit framework and incorporated concepts from the socioecological model^35^ in keeping with a frequent need to combine multiple frameworks in this analytic approach.^32,33^ In Figure 2, we keep the patient at the center to acknowledge that, while not the focus of this analysis, the patient benefits or incurs adverse outcomes from QI activities conducted within this framework. To operationalize the high-level CFIR domains in the context of transformational coaching, we established domain-level definitions (Appendix E). We also consulted with the lead developer of CFIR (a member of our TEP) in the process of adapting CFIR for this review and during the development of our coding approach for this KQ.

Figure 2 Consolidated Framework for Implementation Research (Adapted)

Because KQ 2 was framed around the identification of barriers and facilitators to the uptake of transformational coaching, we conducted an initial round of coding into 2 conceptual buckets: barriers and facilitators. We defined barriers as activities/events/conditions that the coach is facing when working with teams that impede coaching activities related to QI activities and projects. We defined facilitators as something that the coach does (or existing conditions) that helps to enable the coaching process around QI projects (including what the coach does to overcome barriers). While these definitions combine organizational facilitators and coach-level actions to overcome barriers, we included both given their direct applicability to the KQ.

Initially, the KQ 2 team coded 2 articles with these barrier/facilitator codes. We compared and refined our coding approach until an acceptable level of consistency was achieved. We then divided the included articles across pairs from a smaller group of investigators (SR, AL, SH, KG) and applied our operationalized CFIR domains (context, transformational coaching intervention characteristics, team/individual characteristics, QI project/process, and patient) across barriers and facilitators. Each member of the pair reviewed the codes of the other. To ensure rigor and validity, we generated themes for barriers and facilitators by CFIR domains first individually, then within pairs and then mapped these themes to constructs within CFIR domains. We then discussed all coding in the smaller coding group until consensus across the 4 investigators in the smaller group was reached. In addition, throughout this process, we met regularly as a small group to discuss areas of discrepancy until agreement was reached. The qualitative team use Nvivo software to support first- and second-level coding and analysis (QSR International Pty Ltd, Version 12, 2018).

## RATING THE BODY OF EVIDENCE

For KQ 1, the certainty of evidence for each key question was assessed using the approach described by the Grading of Recommendations Assessment, Development and Evaluation (GRADE).^36^ We limited GRADE ratings to those outcomes identified by the stakeholder and TEP as critical for decision making. This approach requires assessment of 4 domains: ROB, consistency, directness, and precision. Additional domains used when appropriate are coherence, dose-response association, impact of plausible residual confounders, strength of association (magnitude of effect), and publication bias. These domains were considered qualitatively, and a summary rating was assigned after discussion by 2 investigators as high, moderate, or low certainty of evidence. In some cases, high, moderate, or low ratings were impossible or imprudent to make. In these situations, a grade of very low certainty of evidence was assigned.

For KQ 2, we assessed the certainty of evidence using the Confidence in the Evidence from Reviews of Qualitative Research (GRADE-CERQual) (Appendix F).^37^ Given the large number of findings across a total of 15 CFIR constructs, we had our operational partners prioritize the 5 constructs most critical for decision making for application of CERQual.^37^ The CERQual approach requires assessment across 4 components: methodological limitations, coherence, adequacy of data, and relevance. A subgroup of investigators with qualitative methods expertise (SR, AL, SH, KG) determined the assessment of these components and subsequently the overall assessment for each finding as a group through consensus.

## PEER REVIEW

A draft version of this report was reviewed by technical experts and clinical leadership. A transcript of their comments and our responses is in Appendix G.

## GLOSSARY

Refer to the glossary in Appendix H for additional terms and definitions.