# APPENDIX H GLOSSARY

For full study citations in this appendix, please refer to the report’s main reference list.

Certainty of evidence: We assessed the certainty of evidence using the Grading of Recommendations Assessment, Development and Evaluation (GRADE) approach^36^ for 4 domains:
  Domain | Rating | How Assessed
  Risk of bias | Low; Unclear; High | Assessed primarily through study design and aggregate study quality
  Consistency | Not serious inconsistency; Serious inconsistency; Very serious inconsistency | Assessed primarily through whether effect sizes are generally on the same side of “no effect,” the overall range of effect sizes, and statistical measures of heterogeneity
  Directness | Not indirect; Serious indirectness; Very serious indirectness | Assessed by whether the evidence involves direct comparisons or indirect comparisons through use of surrogate outcomes or use of separate bodies of evidence
  Precision | Not serious imprecision; Serious imprecision; Very serious imprecision | Based primarily on the size of the confidence intervals of effect estimates, the optimal information size and considerations of whether the confidence interval crossed a clinical decision threshold
  Summary certainty of evidence ratings for a body of evidence:
  - High—High confidence that the true effect lies close to that of the estimate of the effect.
  - Moderate—Moderate confidence in the effect estimate. The true effect is likely to be close to the estimate of the effect, but there is a possibility that it is substantially different.
  - Low—Limited confidence in the effect estimate. The true effect may be substantially different from the estimate of the effect.
  - Very low—Very little confidence in the effect estimate. The true effect is likely to be substantially different from the estimate of effect.
  - Insufficient—Impossible or imprudent to rate. In these situations, a rating of insufficient is assigned.
CERQual (Confidence in the Evidence from Reviews of Qualitative Research): We assessed confidence in the evidence from using the Grading of Recommendations Assessment, Development and Evaluation (GRADE) CERQual approach^36^ ^,37^ for 4 domains:
  Domain | Rating | How Assessed
  Methodologi; cal; Limitations | No limitations; Minor limitations,; Moderate limitations,; Significant limitations | The extent to which there are problems in the design or conduct of the primary studies supporting a review finding
  Relevance | No concerns,; Minor concerns,; Moderate concerns,; Significant concerns | The extent to which the body of evidence from the primary studies supporting a review finding is applicable to the context specified in the review question
  Coherence | No concerns,; Minor concerns,; Moderate concerns, Significant concerns | An assessment of how clear and cogent the fit is between the data from the primary studies and the review finding
  Adequacy | No concerns,; Minor concerns,; Moderate concerns,; Significant concerns | The degree of richness and quantity of data supporting a review finding
  Summary confidence of evidence ratings:
  - High confidence: It is highly likely that the review finding is a reasonable representation of the phenomenon of interest
  - Moderate confidence: It is likely that the review finding is a reasonable representation of the phenomenon of interest
  - Low confidence: It is possible that the review finding is a reasonable representation of the phenomenon of interest
  - Very low confidence: It is not clear whether the review finding is a reasonable representation of the phenomenon of interest
Objective outcomes (ie, non–patient-reported outcomes): Measures that are not subject to a large degree of individual interpretation and are likely to be reliably measured across patients in a study, by different health care providers, and over time.
Patient-reported outcomes: Outcomes that are directly reported by the patient without interpretation of the patient’s response by a clinician or anyone else and pertains to the patient’s health, quality of life, or functional status associated with health care or treatment.
Risk of bias (ROB): An assessment of study quality. We used the following guidance in this report.
  (1) For KQ 1, we used the Cochrane EPOC ROB tool,^23^ which is applicable to randomized and nonrandomized studies:
  - Randomization and allocation concealment
  - Comparability of groups at baseline
  - Blinded outcomes assessment
  - Completeness of follow-up and differential loss to follow-up
  - Whether incomplete data were addressed appropriately
  - Protection against contamination
  - Selective outcomes reporting
  - Intervention independent from other changes (specific to interrupted time series)
  - Intervention pre-specified (specific to interrupted time series)
  - Intervention effect on data collection (specific to interrupted time series)
  Summary ROB ratings for a study:
  - Low ROB—Bias, if present, is unlikely to alter the results seriously
  - Unclear ROB—Bias that raises some doubts about the results
  - High ROB—Bias that may alter the results seriously
  (2) For KQ 2, we used the Critical Appraisal Skills Programme (CASP) tool^26^ :
  - Validity of study results (clarity of aims, appropriate methodology/design/data collection)
  - Nature of the results (ethical consideration, rigorous data analysis, clarity of findings),
  - Helpfulness of the results (local value).
  No summary ROB was possible for the CASP.