# APPENDIX G PEER REVIEW COMMENTS AND RESPONSE TABLE

Question Text | Reviewer Number | Comment | Section of report | Response
Are the objectives, scope, and methods for this review clearly described? | 1 | Yes | | Acknowledged
Are the objectives, scope, and methods for this review clearly described? | 2 | Yes | | Acknowledged
Are the objectives, scope, and methods for this review clearly described? | 3 | Yes | | Acknowledged
Are the objectives, scope, and methods for this review clearly described? | 4 | Yes | | Acknowledged
Are the objectives, scope, and methods for this review clearly described? | 5 | No - This Review was commissioned to systematically examine quality improvement (QI) studies employing team-based quality improvement coaching interventions. Thus, findings from this synthesis should provide VA operational partners with a better understanding regarding how to assess process and clinical outcomes of VA transformational coaching (TC) approach and, to understand relevant contextual factors (barriers and facilitators) influencing coaching effectiveness. | | We appreciate the reviewer’s thoughtful consideration of this report. The scope of this project, as co-developed by the nominating operations partners, was to focus on particular types of team-based QI innovations that are similar to the model of Transformational Coaching used within the VA system. We address and synthesize the evidence on: the effects of coaching on process outcomes (KQ 1b), the types of outcomes assessed (KQ 1a) and barriers and facilitators to the uptake of transformational coaching-like interventions (KQ 2).
Are the objectives, scope, and methods for this review clearly described? | 5 | To paraphrase p. 11, lines 21–22, for the results of this project to be relevant to other health care organizations, a number of major and minor points warrant further consideration by the authors:; Major Points; 1. Pages 1, 9–10. The Introductory sections of this Report may be confusing to some reader because it is written from a perspective that assumes reader familiarity with a variety of concepts. Specifically, the clarity and logic flow of these sections could be significantly improved by defining key terms, providing a rationale for selecting (or omitting) specific concepts, and provider strong justification for linking relevant theoretical constructs to TC. Some specific points: | Topic Development section of Executive Summary; Introduction of Executive Summary | Thank you for this recommendation. We have significantly revised introductory sections to clarify key terms, improve clarity, and logic flow.
Are the objectives, scope, and methods for this review clearly described? | 5 | a. What is a working definition of quality or process improvement? It is implied but never stated. In one section, QI is linked to characteristics of high-reliability organizations (p. 1) and as a strategy to achieve the health system quality outcomes outlined by the IOM (p. 9). It would be appropriate to operationally define how QI achieves these aims in both places or to use one clear consistent rationale. Similarly, a brief definition of facilitation is not provided in either section although a definition of practice facilitators is defined on p. 9, lines 21–24. Finally, what is a high reliability organization? | Intro of Exec Sum; Intro of full report, second paragraph; Intro of exec sum, first paragraph | A reference for the Institute for Healthcare Improvement (IHI) definition for QI has been included.; Operational definition of QI has been added to Intro, Exec Summary, as well as a new table (Table 1) to further clarify where QI fits within various scientific approaches to improvement activities.; Facilitation definition added.; References in the introduction to high-reliability organizations have been removed. In the discussion, high reliability organization has been defined and the potential relationship to transformational coaching has been clarified (see page 85).
Are the objectives, scope, and methods for this review clearly described? | 5 | b. It is unclear why the authors chose to focus on “one method” (p. 1, lines 12–13) of providing process improvement/quality improvement support (i.e., facilitation) versus other methods that are included in search criteria (e.g., improvement coaching/improvement advisor). For both VA and non-VA readers, it might be helpful to acknowledge some common approaches to leading team-based QI improvement projects including improvement coaching/advising or, coaching by expert staff trained in Lean, Six Sigma, or other systems redesign methodologies. These approaches actually compete with TC within VHA and it seems odd for them not be formally acknowledged. | | Thank you for this observation. Other commonly used team-based QI coaching strategies have been acknowledged in the Introduction. As Transformational Coaching is not a term commonly used in the peer-reviewed literature, we cast a very wide net in our search logic to obtain a variety of QI support upon which to compare to the model of interest, Transformational Coaching.
Are the objectives, scope, and methods for this review clearly described? | 5 | c. The sequence of logically linking QI to facilitation as well as “practice” facilitation to TC is somewhat in unclear in both sections. The logic in the Executive Summary is pretty hard to follow for readers with less familiarity with implementation science and quality improvement jargon. It does not seem necessary to even address facilitation in the Exec Summary provided that there’s an acknowledgement of the range of approaches to QI coaching that would be familiar to readers and similar to TC. The imprecision of terminology in these two sections may be off-putting to implementation science researchers and serve to undermine the report’s credibility for some potential users. | | We have significantly revised these sections to improve clarity and reduce jargon. Further, we have added clarification that there is a wide-range of approaches to team-based QI coaching strategies.
Are the objectives, scope, and methods for this review clearly described? | 5 | d. For p. 9, a clearer rationale for focusing on AHRQ’s model of facilitation vs. VA QUERI’s would be helpful. There is a strong difference between the two facilitation approaches but the nuances may not be evident for many readers. | Intro of executive summary and Topic development section of full report | Thank you for this recommendation. We have included VA QUERI and AHRQ’s definitions of facilitation and have acknowledged that there are multiple conceptualizations of facilitation.
Are the objectives, scope, and methods for this review clearly described? | 5 | Study question KQ 1a, 1b. (p. 1, 11). It would be enhance the Report if these key questions used the same terminology as Figure 1 and explicitly state the focus of 1a is “process” outcomes and 1b is “clinical” outcomes for TC-like assessments. | Study selection section of executive summary, third paragraph. (Note: KQ 1a and b have been switched in the final report.) | We have aligned the terminology in Figure 1 and adjusted the wording of the key questions to clarify as suggested. Note that for KQ 1a, we did not limit outcomes to “clinical outcomes” but describe all outcomes included in studies meeting KQ 1 eligibility criteria. Figure 1 shows KQ 1a in both the process and clinical outcomes bubbles. This has been clarified in the methods section.
Are the objectives, scope, and methods for this review clearly described? | 5 | Page 2, lines 42–47. Please provide clarification in the methods as to why the authors did not include quantitatively assessed barriers and facilitators to transformational coding (e.g. surveys, assessment instruments). The KQ2 question on p. 1 does not indicate that determinant assessment would rely solely on qualitative data. | Data synthesis and analysis section of executive summary | Our eligibility criteria (as outlined in SPIDER page 23), did allow for studies which used quantitative methodologies for assessment of barriers and facilitators (eg, surveys, observational). In fact, 1 included study was a survey that used open-ended questions; (Liddy C, Singh J, Guo M, et al. Physician perspectives on a tailored multifaceted primary care practice facilitation intervention for improvement of cardiovascular care. Fam Pract. 2016;33(1):89–94). This has been clarified in the methods and results sections.; Of note, we did identify multiple studies in our search that assessed the barriers and facilitators for the effectiveness of the QI project itself, but not the adoption of the coach-like role, so were thus excluded.
Are the objectives, scope, and methods for this review clearly described? | 5 | 4. Page 3, Data Synthesis and Analysis. It is unfortunate that this synthesis missed a significant opportunity to evaluate K1 metrics with respect to recommendations by the American College of Physicians to assessing the importance, appropriateness, clinical evidence, specifications, feasibility and applicability of potential performance metrics (Maclean, Kerr, Qaseem, 2018; NEJM) - most measures fail these criteria.; Furthermore, numerous AHRQ studies pertaining to QI initiatives in primary care practice settings find a bias toward utilization and access metrics preferred by senior operational leaders that are neither meaningful or actionable by frontline providers, the people actually doing the QI work (e.g., Gray, Yakir, Hung, 2018). Helping teams and clinical leaders to selecting the appropriate ensemble of K1 measures is difficult for many primary care QI initiatives. In interpreting findings from this synthesis, the authors should | | We agree that specific outcome metrics used to measure the success of a QI project and/or performance measure should be chosen thoughtfully and be valid for the context in which they are used. The scope of investigation and choice of outcomes for this review was informed by preferences from our operational partners and with guidance from our technical expert panel and multidisciplinary investigator team. Unfortunately, conducting a formal assessment of the outcomes identified in KQ 1a using criteria such as those put forth by the ACP in the identified article is out of scope for this current review. We agree that such an evaluation would be an important next step in building an understanding of how to best measure the impact of transformational coaching, and is a step that could be paired with improved stakeholder engagement to
Are the objectives, scope, and methods for this review clearly described? | 5 | acknowledge this limitation or else err in summarizing meaningless measures.; 5. Page 18, KQ 1b. Mapping outcomes at multiple levels should be mentioned earlier in report. | Data synthesis section of the full report, KQ1b(KQ1a in final report) paragraph | ensure the use of relevant and valid metrics. We have noted this in the discussion and limitations.Descriptions of mapping at multiple levels has been emphasized in the executive summary and methods of main report.
Are the objectives, scope, and methods for this review clearly described? | 5 | Page 54. KQ 2 findings. This section seems to conflate organizational barriers and facilitating contextual factors with TC implementation strategies/actions to mitigate B&Fs; these are two distinctly different evaluative questions. Consequently, framing of results in this section is flawed by mixing these two conceptually different constructs.; As noted below in Minor suggestions, optimizing the selection of a practice-based determinants framework (e.g., Tailored Implementation for Chronic Disease framework (Flottorp, Oxman, Krause, et al., 2013 Implem Sci) would like have been more intuitive for readers and for use in categorizing determinants accurately without conflating implementation strategies with enabling factors. | KQ 2 results section of main report | We acknowledge that both organizational facilitators and coaching-initiated facilitators were included in the results for KQ 2. Both were included in our definition of facilitators. This was an intentional inclusion given the nature of transformational coaching. We felt it was important to identify all facilitators within each of the domains including those introduced by a coach. The coach-initiated facilitators directly impacted the domain for which they were included. We acknowledged this in the methods and limitations of the report.We acknowledge that there are multiple frameworks that could have been chosen as the core of our best fit framework approach to KQ 2, and that other choices could have led to different findings. We have added this consideration to our limitations section. In addition, we have clarified our rationale for the selection of CFIR as the core framework for this analysis in the methods section.
Are the objectives, scope, and methods for this review clearly described? | 5 | 7.; Minor:; 1. Page 2, line 33. Define EPOC upon first use. | Study selection section of Exec Sum, second paragraph | Thank you. The suggested edit has been made.
Are the objectives, scope, and methods for this review clearly described? | 5 | 2. Page 2, lines 47–49. Be mindful of undefined jargon such as “influencers” and “determinants.“ | Study selection section of Exec Sum, third paragraph | We have rewritten throughout the report to reduce jargon and clarify definitions.
Are the objectives, scope, and methods for this review clearly described? | 5 | 3. Page 3. Line 28; p. 17. No rationale is provided for using the ERIC strategy taxonomy versus common QI frameworks like “change strategies” (i.e., The Improvement Guide by Langley, Moen, Nolan, Norman & Provost, 2009 that defined a 70+ traditional QI strategies). | Data synthesis and analysis of Exec Sum, first paragraph | We have added the rationale or our choice of ERIC strategy taxonomy to the methods section.
Are the objectives, scope, and methods for this review clearly described? | 5 | 4. Page 3 lines 54–60 and page 18. What is a “best fit framework” and why was CFIR selected as the organizational determinants framework? It is not checklist designed to assess primary care practice settings unlike the Tailored Implementation for Chronic Disease framework which was designed specifically for individual and organizational practice determinants. | Data synthesis and analysis of Exec Sum, third paragraph and; Data synthesis section of main report, KQ 2 section | Thank you. We have now explicated the description of the best fit framework in the main methods section and executive summary for clarification. Further, we provide more justification for the choice of CFIR.
Are the objectives, scope, and methods for this review clearly described? | 5 | 5. Page 4, lines 26–28. Search term list seems incomplete versus Appendix B and Table 3 (p.17). Given VA’s longstanding relationship with IHI on major care initiatives, it seems appropriate to cite their terminology (quality improvement coach or advisor) which has been employed for nearly the last 25 years in VHA. | Results section of exec sum, KQ 1a (KQ 1b in final report) section, first paragraph | We appreciate the need for clarification on these lists. The full list of terms used for our literature search are included in full in Appendix A. This collection of terms was identified from existing systematic reviews and exemplar papers, as well as with input from our operational partners and technical expert panel. After execution of the search, we identified additional terms that were searched for independently (see methods section, page 23.) These approaches together include those terms from IHI as the reviewer mentioned.; Table 4 and Appendix B list the terms used by the authors of the included articles that met our eligibility criteria.
Are the objectives, scope, and methods for this review clearly described? | 5 | Page 9, paragraphs 1 and 2. It is unclear what is to be evaluated – it seems to be facilitation or practice facilitation. Seems like introducing TC earlier would be helpful and to acknowledge there are many terms and models for doing team-based coaching. For example, there are close similarities between TC and AHRQ’s practice facilitation including… | Introduction of main report, first two paragraphs | The introduction has been significantly revised to better provide a rational for the focus on Transformational Coaching. Further, we have multiple definitions for facilitation and have added a table to show the breadth of relevant terms we identified for this review.
Are the objectives, scope, and methods for this review clearly described? | 5 | Page 9, line 32. Please refer to VA facilitation as “implementation facilitation.” A more appropriate and current reference would be the Implementation Facilitation guide (ver. 2.0) on the VA QUERI website. | Introduction of main report, third paragraph | Thank you for this information. We have made this revision and included this citation.
Are the objectives, scope, and methods for this review clearly described? | 5 | 8. Page 9, line 51. Rather than “facilitation methods” it would be preferable to be more precise such as “methods for facilitating team-based QI.“ | Introduction of main report, fourth paragraph | Thank you for this suggestion. We have reworded this paragraph and no longer use this terminology.
Are the objectives, scope, and methods for this review clearly described? | 5 | 9. Page 11, TC definition, line 57. Use of external is confusing as used here relative to prior discussion about facilitators being internal or external to a team or healthcare system. Page 12 description on line 46 seems to contradict early discussion that TC/facilitation can be internal or external to a team (p. 9, line 40). Unclear here or elsewhere how TCs “catalyze and build capacity for sustained change” such as through what common principles, methods, skills, framework, etc.? TC seems like a black box intervention and not a well operationalized role and skill set. | Definition and conceptual model section of main report, first paragraph and third paragraph; Introduction of main report, third paragraph | We appreciate that this topic requires clarity around language used given the overlapping fields of study and practice related to this subject matter. Because the definition of transformational coaching is something directly informed by, and developed with, the VA operations partners, we did not make further changes. However, we clarify the meaning of ‘external’ in the methods.We agree that the wording was confusing and have corrected it for consistency.
Are the objectives, scope, and methods for this review clearly described? | 5 | 10. Pages 10…11. The language pertaining to the use of the words “process (es)” and “outcome(s)” is used broadly. Greater precision and specificity would be welcome to help clarify term use in specific context (i.e., operationally defining these terms for purposes of this report). | Topic development section of main report | As noted above, we appreciate the importance of clarity around wording and have refined the definitions and language as suggested.
Are the objectives, scope, and methods for this review clearly described? | 5 | 11. Page 12, lines 48–49. New use of processes of care and clinical outcome terms without clear definition. | Definition and conceptual model of main report, fourth paragraph | Definitions and wording choices have been aligned.
Are the objectives, scope, and methods for this review clearly described? | 5 | 12. Page 12, lines 55–56. “…multiple determinants to the ‘adoption’ of TC…” It seems like KQ2 from the proceeding page mentioned the implementation and adoption of TC (order of terms should likely be reversed). These terms are being used imprecisely to describe the process of implementing a QI process/initiative. The authors are cautioned about using terms that refer to specific sequential steps in an implementation process, loosely. It seems like “adoption” in this report is a term borrowed from program evaluation frameworks like RE-AIM but which is different than its use in other implementation science contexts. | Definition and conceptual model of main report, fourth paragraph | Thank you. The model does focus on the overall uptake of transformational coaching, so the statement was amended to reflect this.
Are the objectives, scope, and methods for this review clearly described? | 5 | 13. Page 14, lines 8–9. “not necessarily” seems like imprecise wording for inclusion criteria (see Table 2 use as well). The Intervention exclusion criteria do not seem consistently applied. Many of the studies examined for K1 seem to be complex, multicomponent interventions per definition by the UK’s MRC (e.g., guideline implementation) and there is reference to studies that used learning collaboratives (pp. 25 ). Not defining these terms precisely in this table seems to have created lapses in criteria being used consistently, affecting results. Outcomes on Table 1 seem outlined for K1a only and do not mention clinical outcomes of interest. How are constructs like self-efficacy and team member knowledge defined? | Study eligibility criteria table, intervention (and phenom. of interest) item 1.Table 4. transformational coaching activities | We have revised the inclusion criteria language to note that individuals in the coaching-like role were not required to be an expert on the clinical topic of relevance to a given QI project, though they could be.; We acknowledge that transformational coaching is a complex intervention and thus the eligible studies included in this review were also complex interventions. We aimed to identify those studies which were consistent with transformational coaching as defined by the review’s operational partners without including those studies which had significant co-delivered interventions which would preclude isolation of effect due to the coaching-like intervention. While we sought to develop clear rules to support making this distinction (eg, excluding longitudinal learning collaboratives vs including one-time learning collaboratives). We recognize that this may have excluded studies that potentially relevant information and have acknowledged this in the limitations.; Definitions for self-efficacy and team member knowledge have been added to Table 2.
Are the objectives, scope, and methods for this review clearly described? | 5 | 14. Page 17. Please explain the cause of the discrepancy in term use between K1 and K2 in Table 3. | Table 3. Other terms for transformational coaching | Table 4. shows the terms for the coach-like role used by the studies included in KQ 1 versus KQ 2. Because there were different studies included for each KQ, the terms are different as well. We have adjusted the title for this table for clarity
Are the objectives, scope, and methods for this review clearly described? | 5 | 15. Page 17, KQ1, line 43. Why were ERIC strategies used describe the methods use to make a QI process or clinical improvement rather than “other commonly used terms to enact change on sources of waste, inefficiency, barriers, etc. such as countermeasures, redesigns, change strategies, drivers, etc.? Given the lack of clarity about what a TC does with teams to help coach them to QI change, it’s hard to determine whether ERIC is appropriate or not. | Data Synthesis of main report, KQ 1b section, first paragraph | We chose to use the ERIC strategies to show the range of implementation activities that the coaches were involved with and to align with other facilitation research. We have added language to the methods to outline our rationale for choosing this particular taxonomy.
Are the objectives, scope, and methods for this review clearly described? | 5 | 16. Page 19, lines 49–59. Use of term over-read is awkward. Could less jargon be employed here for readability? Also, how many coders were needed to achieve consensus on codes/themes? | Data Synthesis of main report, KQ 2 section, third paragraph | We have refined the language here as recommended and clarified expectations for consensus.
Are the objectives, scope, and methods for this review clearly described? | 5 | 17. Pages 24–25, Table 4. It would be more intuitive to list implementation strategies by likely first use over the chronological timespan of a typical QI project. It is unclear if “operationalized definition” comes from ERIC studies, recent AHRQ evaluation by Perry, Damschroder et al., or an internal definition developed by this ESP team. | Table 4. Transformational Coaching Activities | We have reordered this table (now Table 5) as suggested.Clarification that the operationalized definitions were modified from the ERIC study has been added as a footnote.
Are the objectives, scope, and methods for this review clearly described? | 5 | 18. Page 25, lines 55–57. As noted by the AHRQ evaluators of EvidenceNow effort, audit and feedback are two distinctly separate strategies. See Perry, Damschroder, Hemler et al., 2019 Implem Sci. | Transformational Coaching Activities, KQ1 results, main report, second paragraph | We have acknowledged that these are distinct strategies, however list them together as that is the way they were typically described in the included studies.
Are the objectives, scope, and methods for this review clearly described? | 5 | 19. Page 29m Bottom Line. Was the ultimate problem that a clear performance benchmark was never set at the beginning of a QI project so that improvement relative to a goal was difficult to ascertain? See importance of distinguishing between audit and feedback for monitoring and accountability. Is this an issue of knowledge, literacy and proficiency in collecting the right data or being able to analyze it and digest in a manner to support systematic, iterative improvements in key goal targets for improvement? | Goal attainment section of main report, Detailed findings KQ 1b, bottom line box | We agree that this is an important question; however, we are unable to adequately address it based on the 2 studies with relevant outcomes for this section. We have noted the importance of thoughtful selection of valid and relevant outcomes for tracking success as noted in a previous response.
Are the objectives, scope, and methods for this review clearly described? | 5 | 20. Page 30, lines 10–11. Implementation of national preventive guidelines seems like a complex, multi-component intervention which should have been excluded per study criteria. | Adoption of Targeted Process of Care Activities, National preventative care guidelines, Detailed Findings KQ 1b | We recognize that the term “multi-component’ was unclear and have removed it from the inclusion criteria. Transformational coaching is a complex intervention, thus the included intervention were complex. However, we excluded those interventions which included co-delivery of strategies that are not part of the definition of transformational coaching and which would preclude the isolation of treatment effect for the coach-like intervention component.
Are the objectives, scope, and methods for this review clearly described? | 5 | 21. Page 30, line 29. Spell out number 1. | National preventative care guidelines,Detailed Findings KQ 1b, second paragraph | Thank you for your comment.
Are the objectives, scope, and methods for this review clearly described? | 5 | 22. Page 33. There is a considerable amount of jargon in this section – organizational structures, continuous QI framework, practice management, etc. As in defining reach on (line 49), it would be helpful to define less commonly understood terms like organization structures. | Organizational Process of Care, third paragraph | Thank you for this recommendation. We have removed unnecessary jargon and defined the remaining terms (continuous QI framework, practice management).
Are the objectives, scope, and methods for this review clearly described? | 5 | 23. Page 35, line 11. How did studies with learning collaboratives get included in the Results if learning or quality improvement collaboratives are considered an exclusion criterion? | Appropriate documentation, first paragraph | We have clarified that learning collaboratives were only a cause for exclusion if the effect of coaching was not able to be isolated.We agree that exploring the effect of coaching with learning collaboratives could be helpful; however, this was not within the scope of the key questions for this review.
Are the objectives, scope, and methods for this review clearly described? | 5 | 24. Page 54, 3rd bullet. While this point seems evident, the language is so broad here that it is difficult to interpret what “knowledge of the change processes required to implement QI…” is relative to expert credentials or skills needed by a TC. | KQ2 results section, Key Points | We have revised this statement and address the coach outcomes for the team to be successful.
Are the objectives, scope, and methods for this review clearly described? | 7 | Yes | | Acknowledged
Is there any indication of bias in our synthesis of the evidence? | 1 | No | | Acknowledged
Is there any indication of bias in our synthesis of the evidence? | 2 | No | | Acknowledged
Is there any indication of bias in our synthesis of the evidence? | 3 | No | | Acknowledged
Is there any indication of bias in our synthesis of the evidence? | 4 | No | | Acknowledged
Is there any indication of bias in our synthesis of the evidence? | 5 | No | | Acknowledged
Is there any indication of bias in our synthesis of the evidence? | 7 | No | | Acknowledged
Are there any published or unpublished studies that we may have overlooked? | 1 | No | | Acknowledged
Are there any published or unpublished studies that we may have overlooked? | 2 | Yes - See comment regarding exclusion of studies that used a collaborative improvement process | | We have clarified that learning collaboratives were only a cause for exclusion if the effect of coaching was not able to be isolated.; We agree that exploring the effect of coaching with learning collaboratives could be helpful; however, this was not within the scope of the key questions for this review
Are there any published or unpublished studies that we may have overlooked? | 3 | Yes - As I said in the other e-mail, I believe the search term “Transitional Coaching” do not have a standard definition. I suspect that Performance Improvement Literature with the associated roles of an improvement advisor, or facilitator, or PI coach, etc. have a huge overlap with this role. In addition, I wonder if the transitional coaching role emphasizes the people part of improvement more (I think it does) and the PI tools less (not sure). I wonder if T.C. is a VA term, or if it is really spread outside of VA. While I don’t have a lot of insight into that (nor specific articles to suggest), just wanted to express that as a potential concern here, thank you | | The reviewer is correct that transformational coaching is a VA term for a role that is conceptualized in similar ways outside of the VA. For the purposes of this report, we worked with our operational partners to develop a definition of transformational coaching -against which we could compare and identify similar interventions in the published literature.
Are there any published or unpublished studies that we may have overlooked? | 4 | No | | Acknowledged
Are there any published or unpublished studies that we may have overlooked? | 5 | No | | Acknowledged
Are there any published or unpublished studies that we may have overlooked? | 7 | No | | Acknowledged
Additional suggestions or comments can be provided below. If applicable, pleaseindicate the page and line numbers from the draft report. | 1 | Thank you for the opportunity to review this ESP report on transformational coaching. This was an ambitious undertaking with potential important findings. I would say my main recommendation is to distill results down considerably and carefully align tables and text. This is very challenging to work through and the flow can be improved. I’ve provided suggestions here. | | Acknowledged
Additional suggestions or comments can be provided below. If applicable, pleaseindicate the page and line numbers from the draft report. | 1 | Executive Summary; - The language around presenting findings in terms of “COE” level is confusing. It may help readers if the authors identified barriers and facilitators and then tagged each parenthetically with COE level. For example, “high workload was a barrier (moderate COE)…” etc. | KQ2 results section, exec sum, third paragraph | We have clarified this language in the executive summary.
Additional suggestions or comments can be provided below. If applicable, pleaseindicate the page and line numbers from the draft report. | 1 | Applicability; - Clarify that nearly all studies were in primary care settings (including the one in the VA). Making a blanket statement about applicability to VA is overly broad; it seems that applicability needs to be limited to primary care settings. | Discussion section of exec sum, Applicability section | This qualification has been added as suggested.
Additional suggestions or comments can be provided below. If applicable, pleaseindicate the page and line numbers from the draft report. | 1 | Introduction; - Move the KQs to Introduction. The section ends with a paragraph that seeks to summarize the aims but the description here does not quite match the KQs under Methods. E.g., assessing effects on clinical care delivery processes versus effects on team-based goal attainment, etc. | Introduction section, main report, fourth paragraph | The KQs have been moved as recommended.
Additional suggestions or comments can be provided below. If applicable, pleaseindicate the page and line numbers from the draft report. | 1 | Methods; - Figure 1: KQ 1 a focused on effects of TC while KQ 1b focuses on types of outcomes-the diagram (and corresponding text) confuses this distinction | Transformational Coaching Conceptual Model | We have adjusted the language in the KQs and the conceptual model description to reflect that KQ 1 was focused on the effect of transformational coaching on process of care outcomes and KQ 2 was focused on the mapping and grouping of all measured outcomes across patient, provider and practice level outcomes.
Additional suggestions or comments can be provided below. If applicable, pleaseindicate the page and line numbers from the draft report. | 1 | Nice Table 1 that really helps the reader understand the operationalization of TC, which is a rather diffusely defined intervention; - Combining tables 1 and 2 with an extra column to indicate which KQs apply would be helpful. As is, I must compare the tables to see where the differences are | Study eligibility criteria for KQ1 and 2 | We appreciate that these 2 tables may add some confusion. However, they use separate criteria as appropriate for quantitative and qualitative evidence synthesis, they are incompatible for reducing to a single table.
Additional suggestions or comments can be provided below. If applicable, pleaseindicate the page and line numbers from the draft report. | 1 | This is a picky point, but the ERIC list comprises strategies, not categories of strategies | Data synthesis KQ 1a section, first paragraph | Thank you, this wording has been changed.
Additional suggestions or comments can be provided below. If applicable, pleaseindicate the page and line numbers from the draft report. | 1 | Your definition of “facilitators” seems problematic: You say that your “Key Question was framed around the identification of barriers and facilitators to the implementation of transformational coaching…” but then go on to define facilitators as “as something that the coach does (or existing conditions) that helps to enable the coaching process around QI projects (including what the coach does to overcome barriers).” This is confusing and conflates the function of the THING (transformational coaching) that is being implemented with *facilitators* of that implementation. To put “existing conditions” (these might be true contextual facilitators for implementation) and “what the coach does” also, as a facilitator, blurs the line. | Data synthesis, KQ 2 section, Second paragraph | We have clarified the wording throughout the report and added a table in the introduction to clarify terminology used.
Additional suggestions or comments can be provided below. If applicable, pleaseindicate the page and line numbers from the draft report. | 1 | This is a picky comment: by “over-read” do the authors mean that a 2^nd^ reviewer read the article? This should be stated. “Over-read” doesn’t convey this idea. | Data synthesis, KQ 2 section, third paragraph | Thank you, this wording has been revised.
Additional suggestions or comments can be provided below. If applicable, pleaseindicate the page and line numbers from the draft report. | 1 | Why not rate COE for all 15 CFIR constructs? We have worked with ops partners to ID “high priority” constructs and discovered that though some came to be empirically verified, others turned out not to be high priority and still others were on the empirically derived list that were not ID’d as “high priority” by our partners | Rating the body of evidence, second paragraph | This topic and our report was driven by our nominating stakeholders’ information needs. We routinely survey our stakeholders to request prioritization of key outcomes for COE across all our reports and this is a routine practice in systematic reviews when it is infeasible due to team capacity to conduct COE for all identified outcomes. Thus, we elected to work with our operational partners who requested this review to select those constructs deemed of greatest relevance to them. We acknowledge that this may not reflect the most important constructs in other contexts or as perceived by other stakeholders. We have added a statement to this effect in the limitations.
Additional suggestions or comments can be provided below. If applicable, pleaseindicate the page and line numbers from the draft report. | 1 | Results; - Suggest rearranging this section to provide results for KQ1, including the PRISM diagrams, followed by KQ2 and divide (following PRISM for KQ1a) sections for 1a versus 1b (i.e., p23, move KQ 1b down to a separate subsection | Results, main report | We have moved the literature flow diagram for KQ 2 to the beginning of the KQ 2 section as suggested and separated the KQ 1b into its own subsection.
Additional suggestions or comments can be provided below. If applicable, pleaseindicate the page and line numbers from the draft report. | 1 | In Table 4, suggest adding number of studies with documented use of each ERIC strategy | Table 4 Transformational Coaching Activities | The number of studies that used each coaching strategy has been added to Table 5 (formerly Table 4).
Additional suggestions or comments can be provided below. If applicable, pleaseindicate the page and line numbers from the draft report. | 1 | Table 5 can be moved to an Appendix | Table 5 Implementation strategies | Thank you for this helpful suggestion. We have moved Table 5 to Appendix C.
Additional suggestions or comments can be provided below. If applicable, pleaseindicate the page and line numbers from the draft report. | 1 | For Goal Attainment (p29), the bottom line seems to be that TC doesn’t have an effect…though one low ROB study did find a positive effect. The other study with high ROB found no effect. | KQ 1a results section, goal attainment section | For this outcome, 1 study at unclear ROB found a significant improvement in the number of QI projects initiated. The second study at high ROB found no effect. Thus, our conclusion was mixed effect.
Additional suggestions or comments can be provided below. If applicable, pleaseindicate the page and line numbers from the draft report. | 1 | For the “Adoption of Targeted Process of Care Activities” section, Bottom Line states there were 6 trials but the 3^rd^ sentence refers to 7 trials. This summary should highlight that 6 of 7 studies had low/unclear ROB. | KQ 1a results section, Adoption of Targeted Process of Care Activities | Thank you, this section has been clarified.
Additional suggestions or comments can be provided below. If applicable, pleaseindicate the page and line numbers from the draft report. | 1 | Suggest significantly distilling this section to consolidate all outcome types to a single Bottom Line. The number of studies within each category are small and the particular topics don’t really have meaning because the focus is on TC. Tables 6–11 can be combined into a single table – possibly pushed to an appendix. | Effects of Transformational Coaching on X tables | We have refined the key points for KQ 1a to provide a clearer overall outcome conclusion. However, we have retained the individual tables as the analysis was structured to provide some granularity across types of clinical activities around which a coach might engage with a clinical team. This approach differed from previous analysis of coaching-like interventions and so we believe adds to the existing literature.
Additional suggestions or comments can be provided below. If applicable, pleaseindicate the page and line numbers from the draft report. | 1 | Suggest moving the summary of ROB (p45) before sections on outcomes. This way all outcomes are interpreted within context of overall ROB. Likewise, move the COE section (p47) to follow the ROB section. | Quality of Evidence KQ 1a Studies sectionCertainty of Evidence for Key Question 1a | The order of these sections was maintained to be consistent with ESP standard formatting.
Additional suggestions or comments can be provided below. If applicable, pleaseindicate the page and line numbers from the draft report. | 1 | Bottom Line on p33, 2^nd^ sentence is unclear | Organizational Processes of Care | This sentence has been rewritten.
Additional suggestions or comments can be provided below. If applicable, pleaseindicate the page and line numbers from the draft report. | 1 | Figure 6 - add n=number of studies | Figure 6. Risk of Bias Assessment Across Included Cohort Studies in KQ 1a | The number of included studies has been added to the figure title.
Additional suggestions or comments can be provided below. If applicable, pleaseindicate the page and line numbers from the draft report. | 1 | The above recommended rearrangement is reinforced by the fact that KQ1b then goes into great detail about the types of outcomes. Is it possible to rearrange KQ1a–1b to reverse the order? It would flow better to first ID types of outcomes (1b flipped into the new 1a) and then provide results on effects across those outcomes (and referring to the detailed table by type of outcome) | | We have switched the order of KQ 1a and KQ1b.
Additional suggestions or comments can be provided below. If applicable, pleaseindicate the page and line numbers from the draft report. | 1 | KQ2; - Which studies overlapped with studies ID’d for KQ1a–b? | | There are 2 studies in common between KQ 1a and KQ 2. This information has been added to the report in the results section of KQ 2.
Additional suggestions or comments can be provided below. If applicable, pleaseindicate the page and line numbers from the draft report. | 1 | Figure 7 seems to provide themes/findings. The title should highlight this | Figure 7. Consolidated Framework for Implementation Research: Context | Thank you. The figures for the section on KQ 2 have been reworked and renamed.
Additional suggestions or comments can be provided below. If applicable, pleaseindicate the page and line numbers from the draft report. | 1 | Table 15 should include all B&Fs identified in the text. | Table 15. CERQual Summary of Qualitative Findings Table for KQ 2 | This topic and our report was driven by our nominating stakeholders’ information needs. We routinely survey our stakeholders to request prioritization of key outcomes for COE across all our reports and this is a routine practice in systematic reviews when it is infeasible due to team capacity to conduct COE for all identified outcomes. Thus, we elected to work with our operational partners who requested this review to select those constructs deemed of greatest relevance to them. We acknowledge that this may not reflect the most important constructs in other contexts or as perceived by other stakeholders. We have added a statement to this effect in the limitations.
Additional suggestions or comments can be provided below. If applicable, pleaseindicate the page and line numbers from the draft report. | 1 | It is confusing what is meant by e.g., “we found 1 barrier and no facilitators…an example is…another example is…” What are the examples? Does this mean that more than 1 study had that single barrier? The language here is unclear. | Cosmopolitanism (outer setting); Implementation climate (inner setting) | We revised the language to add clarity that several examples exist under one big barrier for both constructs. The studies supporting each findings are cited in the text.
Additional suggestions or comments can be provided below. If applicable, pleaseindicate the page and line numbers from the draft report. | 1 | Move ROB section earlier in this section. | | The order of these sections was maintained to be consistent with ESP standard formatting.
Additional suggestions or comments can be provided below. If applicable, pleaseindicate the page and line numbers from the draft report. | 1 | The text for Table 15 should be prefaced with the fact that it includes only the 5 constructs chosen by the partners. Link these with the corresponding text in the previous sections. A final summary section could perhaps lightly touch on the other constructs but the details can be relegated to an appendix. It seems important, however, to rate COE for the non-chosen constructs as well.; - Perhaps it missed it, but a rationale/criteria for choosing the 5 constructs is needed. This seems like a lot of work to do (coding for all the other constructs) and then only focus on 5 without any real empirical evidence. | Table 15. CERQual Summary of Qualitative Findings Table for KQ 2 | (Please note that due to other changes, Table 15 is now Table 19). The text prior to Table 19 has been clarified.; This topic and our report was driven by our nominating stakeholders’ information needs. We routinely survey our stakeholders to request prioritization of key outcomes for COE across all our reports and this is a routine practice in systematic reviews when it is infeasible due to team capacity to conduct COE for all identified outcomes. Thus, we elected to work with our operational partners who requested this review to select those constructs deemed of greatest relevance to them. We acknowledge that this may not reflect the most important constructs in other contexts or as perceived by other stakeholders. We have added a statement to this effect in the limitations.
Additional suggestions or comments can be provided below. If applicable, pleaseindicate the page and line numbers from the draft report. | 2 | The ESP Review of Transformation Coaching conducted by the investigators and documented in the report is comprehensive, thorough, detailed and highly valuable to VHA and particularly to those who strive to fully adopt the principles and practices of a high reliability organization. As a member of the TEP, I fully agree with the findings and conclusions reported in the review. Ihave several suggestions that 1 believe will enhance understanding and interpretation of the findings, as well as the limitations that the authors have specified in the report. 1 suggest the authors consider including more details on the key findings in the executive summary as 1 believe this will increase the clarity of the findings, especially for those who don’t take the time to read the detailed results section of the review. | Results section of the executive summary | Thank you for your contributions to the report as a TEP member and your thoughtful review of the draft report. We appreciate this suggestion and have revised the executive summary as suggested.
Additional suggestions or comments can be provided below. If applicable, pleaseindicate the page and line numbers from the draft report. | 2 | For example, in both the Summary of Results for Key Questions (starting on page 4) and the Discussion of Key Findings, starting on page 6, the authors offer fairly high level descriptions of the results. For example, on page 4, line 44, the authors state, “Across outcomes related to adoption of targeted process of care activities, there was very low to low COE that coaching probably has an effect on composite process of care outcomes and ordering of labs and vital signs, and possibly has an effect on changes in organizational process of care and delivery of appropriate counseling. It is uncertain if coaching has an effect on the conduct of specific exams and procedures, and probably does not have an effect on prescription of diagnosis appropriate medications.” Though this is accurate, more detail about the positive findings noted would be valuable. | Summary of Results for Key Questions, exec sum, KQ 1a, second paragraph | We have incorporated more detail in the Executive Summary as suggested.
Additional suggestions or comments can be provided below. If applicable, pleaseindicate the page and line numbers from the draft report. | 2 | Also, on page 6, in the discussion section, line 36, the authors state, “However, we found that coaching probably has an effect on composite process of care outcomes and ordering of labs and vital signs, and possibly has an effect on changes in organizational process of care and delivery of appropriate counseling. It is uncertain if coaching has an effect on the conduct of specific exams and procedures, and probably does not have an effect on prescription of diagnosis-appropriate medications.” Again, more detail regarding the specific outcomes that were achieved by T–coaching might be included here. The Key Points listed on page 23 provide a bit more detail, listing the number of trials for each category of process of care outcomes, though even better yet would be inclusion of at least some of the “Bottom Line findings” for KQ1 which are found in the Detailed Findings section, starting on pg 29. Perhaps the most important results are found in the Bottom Line boxes on page 31, 33, 35 and 37. | Discussion, exec sum, second paragraph | We appreciate these suggestions and have made revisions accordingly.
Additional suggestions or comments can be provided below. If applicable, pleaseindicate the page and line numbers from the draft report. | 2 | The sections KQ2 results in the Executive Summary might also include additional detail regarding specific findings on barriers and facilitators. Limitations and Research Gaps in the Executive Summary are fine, though I suggest adding some of the points made in the section on Clinical Policy Implications, found on page 74, to the Conclusions section of the Executive Summary to make the link between T-Coaching and the broader effort to become a HRO. The final sentence of the Clinical Policy Implications needs to be in the conclusions, line 5774 – “As we describe in this report, coaches can play a critical role in facilitating access to and use of data and technical resources for QI activities.“ | Clinical Policy Implications, Discussion of main report | We appreciate these suggestions and have made revisions accordingly (see second paragraph under KQ 2 in results and the conclusions of Executive Summary).
Additional suggestions or comments can be provided below. If applicable, pleaseindicate the page and line numbers from the draft report. | 2 | Pg 14 – Table 1 - The exclusion criteria includes “Interventions that focus on learning collaborative as the main component of the intervention or have a longitudinal learning collaborative component. Please clarify why a learning collaborative led to exclusion if one could isolate the T-Coaching component across intervention and control conditions. This would allow inclusion of trials that utilized a longitudinal collaborative with or without the addition of a T-Coach assigned to assist a team participating in the collaborative. Since collaboratives offer resources which address many of the barriers found in the analysis of data gathered for KQ2, the addition impact of a coach might be even more valuable in this context. How many of the excluded studies were excluded because of this specific exclusion criteria. What impact might this have had on results? | Table 1. Study Eligibility Criteria for KQ 1; Table 4. Transformational Coaching Activities | We have clarified Table 2 (formerly Table 1) to note that learning collaboratives were only a cause for exclusion /Tthe effect of coaching was not able to be isolated.; We agree that exploring the effect of coaching with learning collaboratives could be helpful; however, this was not within the scope of the key questions for this review.
Additional suggestions or comments can be provided below. If applicable, pleaseindicate the page and line numbers from the draft report. | 2 | Pg 18 – line 41 KQ 1b second order outcomes example includes “increased delivery of patient centered evidence based“. Is something missing? | Data synthesis section, main report, KQ 1b | This section has been revised as suggested.
Additional suggestions or comments can be provided below. If applicable, pleaseindicate the page and line numbers from the draft report. | 2 | Pg 19 – Figure 2 with CFIR elements is very helpful! | Figure 2. Consolidated Framework for Implementation Research (Adapted) | Thank you.
Additional suggestions or comments can be provided below. If applicable, pleaseindicate the page and line numbers from the draft report. | 2 | Pg 30 – line 17; Hogg - Authors reported a mean difference of 2.0. It is not clear what the measure was for this study. | National preventive care guidelines, KQ 1 results, first paragraph | Thank you, this data point has been contextualized.
Additional suggestions or comments can be provided below. If applicable, pleaseindicate the page and line numbers from the draft report. | 2 | Pg 30 – line 34; how were “ratio of ratios” calculated? | National preventive care guidelines, KQ 1 results, third paragraph | This language has been updated for clarity.
Additional suggestions or comments can be provided below. If applicable, pleaseindicate the page and line numbers from the draft report. | 2 | Pg 31 – line 19 – “Among 40 primary care practices (822 patients), the authors found all 3 arms improved by end of intervention; however, the coaching arm based on reflective adaptive process experienced greater improvement in process of care score (4.54 to 4.85) than either the continuous quality improvement arm (3.58 to 4.91; p<0.0001) or the enhanced usual care arm (3.63 to 4.39; p <0.0001).” The reported change in the coaching arm appears to be less than the change in control arms. Is this an error? | Diabetes process of care, KQ 1 results, second paragraph | Thank you for noticing this error. The continuous quality improvement arm and the reflective adaptive process arms have been switched.
Additional suggestions or comments can be provided below. If applicable, pleaseindicate the page and line numbers from the draft report. | 2 | Pg 73 – line 14; consider organizing listing of barriers and facilitators by COE: moderate and high, low, very low COE | Summary and Discussion section of main report, KQ 2, second paragraph | We appreciate this suggestion and have re-ordered from higher level of evidence to lower level of evidence.
Additional suggestions or comments can be provided below. If applicable, pleaseindicate the page and line numbers from the draft report. | 2 | Pg 72 – line 20; “Studies included a median of 5.73 implementation strategies“. This piece of data might be included in the executive summary as it reflects the multi-dimensional quality of T-coaching.; Thanks, again, for the opportunity to participate on the TEP and to review this excellent review and report!! | Summary and Discussion section of main report, KQ 1a, first paragraph | Thank you for this suggestion. This has been added to the executive summary.
Additional suggestions or comments can be provided below. If applicable, pleaseindicate the page and line numbers from the draft report. | 3 | See above and prior e-mail
Additional suggestions or comments can be provided below. If applicable, pleaseindicate the page and line numbers from the draft report. | 4 | None
Additional suggestions or comments can be provided below. If applicable, pleaseindicate the page and line numbers from the draft report. | 5 | See detailed comments above. It is difficult to know if studies were left out or overlooked based on the broad inclusion and exclusion criteria. Most QI studies are not randomized clinical trials so that excludes the majority of the literature. Furthermore, many high quality VA randomized initiatives were likely excluded because they employed a virtual community of care or learning collaborative to foster more rapid learning across participating sites received team-based coaching or facilitation; it is unfortunate to lose those studies. | | We made methodologic choices based on the specific key question put forward for this review (ie, limiting to EPOC criteria studies best suited to address questions of effectiveness). We acknowledge that the broader literature holds valuable information that was not incorporated into this review due to ineligible study design. We have noted this in the limitations.
Additional suggestions or comments can be provided below. If applicable, pleaseindicate the page and line numbers from the draft report. | 7 | Pages referenced are the actual document pages noted on the bottom, not the pdf page identifier, pg. iii, line 3: Dr. Davies is not the National Director of Systems Redesign, this should be removed from his title. | TEP Acknowledgment | Acknowledgments have been updated.
Additional suggestions or comments can be provided below. If applicable, pleaseindicate the page and line numbers from the draft report. | 7 | pg. iv, line 45: question 1a: the a is not capitalized like b is in question B and it is not written as a question, seems to be unfinished? | Table of contents | We have corrected this in the table of contents (abbreviated KQ).
Additional suggestions or comments can be provided below. If applicable, pleaseindicate the page and line numbers from the draft report. | 7 | pg. v, line 41: I am not seeing a reference to KQ1 1B | Table of contents | We have corrected this.
Additional suggestions or comments can be provided below. If applicable, pleaseindicate the page and line numbers from the draft report. | 7 | pg. 1, line 16: there is a period that does not belong there | Intro of exec sum, first paragraph | The Executive Summary has been updated.
Additional suggestions or comments can be provided below. If applicable, pleaseindicate the page and line numbers from the draft report. | 7 | pg. 1, line 51: consistent capitalization or not on the 1 a and 1 b of the questions | Intro of exec sum, KQ1a and KQ1b | 1a and 1b are lowercase.
Additional suggestions or comments can be provided below. If applicable, pleaseindicate the page and line numbers from the draft report. | 7 | 6. pg. 7, line 34: strategies decisions is difficult to read, perhaps strategy decisions | Research gaps section of executive summary | We have changed this to “strategic.“
Additional suggestions or comments can be provided below. If applicable, pleaseindicate the page and line numbers from the draft report. | 7 | pg. 11, line 55: Final definition for transformational coaching was as follows, should this be “is as follows“? | Definition and conceptual model section, main report, first paragraph | We have corrected this text.