# APPENDIX F CERQUAL EVIDENCE PROFILE

For full study citations, please refer to the main report’s reference list.