# APPENDIX E CONSOLIDATED FRAMEWORK FOR IMPLEMENTATION RESEARCH (CFIR) CONSTRUCTS

| Construct | Short Description | Operationalization for Transformational Coaching
I.Intervention Characteristics/Transformational Coach | | | Intervention is the coaching itself and the characteristics that make transformational coaching more or less implementable (eg, modality, the coach as an individual, the act of coaching or how the coach actually interacted with the team members, who is being coached and relevant stakeholders)
C | Relative Advantage | Stakeholders’ perception of the advantage of implementing the intervention versus an alternative solution | Stakeholders’ view on why implementing transformational coaching instead of another intervention would be beneficial
D | Adaptability | The degree to which an intervention can be adapted, tailored, refined, or reinvented to meet local needs | How easily the transformational coaching can be tailored, changed, or adapted to meet the needs of the local interdisciplinary team
G | Design Quality & Packaging | Perceived excellence in how the intervention is bundled, presented, and assembled | How others view the quality and presentation of transformational coaching intervention
H | Cost | Costs of the intervention and costs associated with implementing the intervention including investment, supply, and opportunity costs | How much it costs to implement the coaching intervention
II. Outer Setting | | | Any level outside the transformational coach and the team receiving the coaching (eg, health care policy, health care system in which a team sits, social drivers such as rates of homelessness in patient population served)
B | Cosmopolitanism | The degree to which an organization is networked with other external organizations | The extent to which the team or larger practice is networked with other organizations
D | External Policy & Incentives | A broad construct that includes external strategies to spread interventions, including policy and regulations (governmental or other central entity), external mandates, recommendations and guidelines, pay-for-performance, collaboratives, and public or benchmark reporting | The external policies and incentives to engage with coaching and QI efforts
III. Inner Setting | | | The team unit and clinic level in which the transformational coaching widget is operating (eg, proximal influences of the widget, leaders not a part of the team being coached)
C | Culture | Norms, values, and basic assumptions of a given organization | The workings of an organization in which the interdisciplinary team sits
D | Implementation Climate | The absorptive capacity for change, shared receptivity of involved individuals to an intervention, and the extent to which use of that intervention will be rewarded, supported, and expected within their organization | How well implementation of new ideas is accepted and put into a practice
E | Readiness for Implementation | Tangible and immediate indicators of organizational commitment to its decision to implement an intervention | Indicators that show that the organization is ready and able to change
IV. Characteristics of Individuals and Team | | | The individual or team who is receiving the transformational coaching widget (eg, the individual team members being coached)
A | Knowledge & Beliefs about the Intervention | Individuals’ attitudes toward and value placed on the intervention as well as familiarity with facts, truths, and principles related to the intervention | How individuals feel about transformational coaching and the value placed on it
C | Individual Stage of Change | Characterization of the phase an individual is in, as he or she progresses toward skilled, enthusiastic, and sustained use of the intervention | The stage of change the person is in with respect to engagement with transformational coaching and QI
E | Other Personal Attributes | A broad construct to include other personal traits such as tolerance of ambiguity, intellectual ability, motivation, values, competence, capacity, and learning style | The personal traits of the person(s) receiving the coaching.
V. Process/QI Strategy | | | How the transformational coaching program was put into place within practice (implementation process, not coaching process)
A | Planning | The degree to which a scheme or method of behavior and tasks for implementing an intervention are developed in advance, and the quality of those schemes or methods | How well a protocol of transformational coaching implementation is developed
C | Executing | Carrying out or accomplishing the implementation according to plan | Actually doing the transformational coaching implementation as planned
D | Reflecting & Evaluating | Quantitative and qualitative feedback about the progress and quality of implementation accompanied with regular personal and team debriefing about progress and experience | Looking back about the progress that was made and if the transformational coaching intervention worked