# APPENDIX D EXCLUDED STUDIES

## KEY QUESTION 1

Exclusion Reason

Study | Not full publication/ OECD | Not eligible setting | Not population of interest | Not eligible intervention | Not eligible comparator | Not eligible outcome/ timing | Not eligible design
Ansari, 2003^1^ | | | | ✕
Aspy, 2008^2^ | | | ✕
Asselin, 2017^3^ | | | | | | | ✕
Baskerville, 2001^4^ | ✕
Bitton, 2014^5^ | ✕
Bucknall, 2017^6^ | | | | ✕
Calo, 2019^7^ | | | | ✕
Chakrabarty, 2014^8^ | ✕
Clapp, 2015^9^ | ✕
Connolly, 2018^10^ | | | | | | | ✕
Courtlandt, 2016^11^ | | | | | | | ✕
Deane, 2014^12^ | | | | ✕
Dorr, 2015^13^ | ✕
Due, 2017^14^ | | | | | | | ✕
Echevarria, 2016^15^ | | | | ✕
Eriksson, 2013^16^ | ✕
Filardo, 2009^17^ | | | | ✕
Finkelstein, 2002^18^ | | | | ✕
Ford,2017^19^ | | ✕
Fox, 2011^20^ | ✕
Gannon, 2011^21^ | | | | | | | ✕
Garrard, 2006^22^ | | | | | | | ✕
Gepts, 2018^23^ | ✕
Grunfeld,2013^24^ | | | ✕
Halladay, 2014^25^ | | | | ✕
Harris, 2017^26^ | | | | ✕
Horn, 2010^27^ | | | | | | | ✕
Huguet, 2018^28^ | | | ✕
Hulscher, 2003^29^ | ✕
Hulscher, 1997^30^ | | | | | | | ✕
Jefferies, 2012^31^ | | | ✕
Jenkins, 2008^32^ | ✕
Jennings, 2017^33^ | | | | ✕
Kaplan, 2018^34^ | | | | ✕
Katz, 2014^35^ | | | | ✕
Kirchner, 2014^36^ | | | | ✕
Knierim, 2019^37^ | | | | ✕
Korner, 2018^38^ | ✕
Lannon, 2013^39^ | | | | | | | ✕
Leamy, 2011^40^ | ✕
Leonard, 2017^41^ | | | | | | | ✕
Lindsay, 2015^42^ | | | ✕
McCormack, 2019^43^ | ✕
McNally, 2006^44^ | | | ✕
Meurer, 2011^45^ | | | | | | | ✕
Michaels, 2017^46^ | | | | ✕
Midboe, 2018^47^ | ✕
Modell, 1998^48^ | | | | ✕
Mullen, 2009^49^ | | | ✕
Naccarella, 2016^50^ | | | | ✕
Nagykaldi, 2005^51^ | ✕
Nowalk, 2016^52^ | | | ✕
Parchman, 2019^53^ | | | | ✕
Parchman, 2008^54^ | ✕
Pearlman, 2002^55^ | | ✕
Persson,2013^56^ | ✕
Petro-Nustas, 1996^57^ | ✕
Rakhmanova, 2016^58^ | ✕
Rantz, 2017^59^ | | | | ✕
Roderick, 2017^60^ | | | | | ✕
Ruhe, 2005^61^ | | | | | | | ✕
Salbach, 2014^62^ | ✕
Sarin, 2018^63^ | | | ✕
Schiff, 2017^64^ | | | | ✕
Schmidt, 1998^65^ | | | | ✕
Siman, 2018^66^ | ✕
Smith, 2019^67^ | | | | ✕
Solberg, 1998^68^ | | | | ✕
Starkey, 2016^69^ | | | ✕
Steiner, 2010^70^ | ✕
Thom, 2016^71^ | | | ✕
Trott, 1999^72^ | ✕
Verreault, 2018^73^ | | | | ✕
Vos, 2010^74^ | | | | ✕
Wray, 2018^75^ | ✕
Zimmerman, 2017^76^ | | | | ✕

### References for KQ 1 Excluded Studies

1 Ansari M, Shlipak MG, Heidenreich PA, . Improving guideline adherence: a randomized trial evaluating strategies to increase beta-blocker use in heart failure. Circulation. 2003;107(22):2799–804.12756157
2 Aspy CB, Enright M, Halstead L, . Improving mammography screening using best practices and practice enhancement assistants: an Oklahoma Physicians Resource/Research Network (OKPRN) study. Journal of the American Board of Family Medicine: JABFM. 2008;21(4):326–33.18612059
3 Asselin J, Salami E, Osunlana AM, . Impact of the 5As Team study on clinical practice in primary care obesity management: a qualitative study. CMAJ open. 2017;5(2):E322–E329.
4 Baskerville NB, Hogg W, Lemelin J. Process evaluation of a tailored multifaceted approach to changing family physician practice patterns improving preventive care. Journal of Family Practice. 2001;50(3):W242–9.
5 Bitton A, Ellner A, Pabo E, . The Harvard Medical School Academic Innovations Collaborative: transforming primary care practice and education. Academic Medicine. 2014;89(9):1239–44.25006712
6 Bucknall TK, Harvey G, Considine J, . Prioritising Responses Of Nurses To deteriorating patient Observations (PRONTO) protocol: testing the effectiveness of a facilitation intervention in a pragmatic, cluster-randomised trial with an embedded process evaluation and cost analysis. Implement Sci. 2017;12(1):85.28693596
7 Calo WA, Gilkey MB, Leeman J, . Coaching primary care clinics for HPV vaccination quality improvement: Comparing in-person and webinar implementation. Translational Behavioral Medicine. 2019;9(1):23–31.29471460
8 Chakrabarty S. Leadership: validation of a self-report scale: comment on Dussault, Frenette, and Fernet (2013). Psychological Reports. 2014;115(2):415–8.25310314
9 Clapp JC. A Multidisciplinary Team Approach to Management of Postpartum Hemorrhage…Proceedings of the 2015 AWHONN Convention. JOGNN: Journal of Obstetric, Gynecologic & Neonatal Nursing. 2015;44:S22–S22.
10 Connolly MJ, Broad JB, Bish T, . Reducing emergency presentations from long-term care: A before-and-after study of a multidisciplinary team intervention. Maturitas. 2018;117:45–50.30314560
11 Courtlandt C, Noonan L, Koricke MW, . Pediatrics Residents’ Confidence and Performance Following a Longitudinal Quality Improvement Curriculum. Journal of Graduate Medical Education. 2016;8(1):74–9.26913107
12 Deane FP, Andresen R, Crowe TP, . A comparison of two coaching approaches to enhance implementation of a recovery-oriented service model. Administration & Policy in Mental Health. 2014;41(5):660–7.23982458
13 Dorr DA, McConnell KJ, Williams MP, . Study protocol: transforming outcomes for patients through medical home evaluation and redesign: a cluster randomized controlled trial to test high value elements for patient-centered medical homes versus quality improvement. Implement Sci. 2015;10:13.25609501
14 Due TD, Thorsen T, Waldorff FB, . Role enactment of facilitation in primary care - a qualitative study. BMC Health Serv Res. 2017;17(1):593.28835276
15 Echevarria M. Translating Knowledge Into Practice Through an Academic-Practice Partnership for Exploring Barriers That Impact Management of Homebound Patients With Heart Failure. Care Management Journals. 2016;17(2):81–96.27298135
16 Eriksson L, Duc DM, Eldh AC, . Lessons learned from stakeholders in a facilitation intervention targeting neonatal health in Quang Ninh province, Vietnam. BMC Pregnancy & Childbirth. 2013;13:234.24330472
17 Filardo G, Nicewander D, Herrin J, . A hospital-randomized controlled trial of a formal quality improvement educational program in rural and small community Texas hospitals: One year results. International Journal for Quality in Health Care. 2009;21(4):225–232.19395710
18 Finkelstein JA, Lozano P, Streiff KA, . Clinical effectiveness research in managed-care systems: lessons from the Pediatric Asthma Care PORT. Patient Outcomes Research Team. Health Services Research. 2002;37(3):775–89.
19 Ford JH, 2nd, Abramson B, Wise M, . Bringing Healthy Aging to Scale: A Randomized Trial of a Quality Improvement Intervention to Increase Adoption of Evidence-Based Health Promotion Programs by Community Partners. J Public Health Manag Pract. 2017;23(5):e17–e24.
20 Fox C, Cadzow R, Cooper B, . Improving chronic kidney disease care in primary care practices. American Journal of Kidney Diseases. 2011;57(4):A40.
21 Gannon M, Qaseem A, Snow V, . Using online learning collaboratives to facilitate practice improvement for COPD: an ACPNet pilot study. American Journal of Medical Quality. 2011;26(3):212–9.21266597
22 Garrard J, Choudary V, Groom H, . Organizational change in management of hepatitis C: evaluation of a CME program. Journal of Continuing Education in the Health Professions. 2006;26(2):145–60.
23 Gepts T, Siman N, Cleland C, . The impact of practice facilitation and seasonal variation on blood pressure control in small independent practices. Circulation. 2018;138.
24 Grunfeld E, Manca D, Moineddin R, . Improving chronic disease prevention and screening in primary care: results of the BETTER pragmatic cluster randomized controlled trial. BMC Fam Pract. 2013;14:175.24252125
25 Halladay JR, DeWalt DA, Wise A, . More extensive implementation of the chronic care model is associated with better lipid control in diabetes. J Am Board Fam Med. 2014;27(1):34–41.24390884
26 Harris MF, Parker SM, Litt J, . An Australian general practice based strategy to improve chronic disease prevention, and its impact on patient reported outcomes: evaluation of the preventive evidence into practice cluster randomised controlled trial. BMC Health Serv Res. 2017;17(1):637.28886739
27 Horn SD, Sharkey SS, Hudak S, . Pressure ulcer prevention in long-term-care facilities: a pilot study implementing standardized nurse aide documentation and feedback reports. Advances in Skin & Wound Care. 2010;23(3):120–31.20177165
28 Huguet N, Hatch B, Sumic A, . Implementation of Health Insurance Support Tools in Community Health Centers. Journal of the American Board of Family Medicine: JABFM. 2018;31(3):410–416.29743224
29 Hulscher ME, Laurant MG, Grol RP. Process evaluation on quality improvement interventions. Quality & Safety in Health Care. 2003;12(1):40–6.12571344
30 Hulscher ME, van Drenth BB, van der Wouden JC, . Changing preventive practice: a controlled trial on the effects of outreach visits to organise prevention of cardiovascular disease. Qual Health Care. 1997;6(1):19–24.10166597
31 Jefferies D, Johnson M, Nicholls D, . Evaluating an intensive ward-based writing coach programme to improve nursing documentation: lessons learned. International Nursing Review. 2012;59(3):394–401.22897192
32 Jenkins P. The role of the nurse educator: mentor, change agent, expert. Journal for nurses in staff development : JNSD : official journal of the National Nursing Staff Development Organization. 2008;24(5):245–247.
33 Jennings RM, Burtner JJ, Pellicer JF, . Reducing Head CT Use for Children With Head Injuries in a Community Emergency Department. Pediatrics. 2017;139(4).
34 Kaplan HC, King E, White BE, . Clinical practice and quality: Statewide quality improvement initiative to reduce early elective deliveries and improve birth registry accuracy. Obstetrics and Gynecology. 2018;131(4):688–695.29528918
35 Katz DA, Holman JE, Johnson SR, . Implementing Best Evidence in Smoking Cessation Treatment for Hospitalized Veterans: Results from the VA-BEST Trial. Joint Commission Journal on Quality & Patient Safety. 2014;40(11):493–1.26111367
36 Kirchner JE, Ritchie MJ, Pitcock JA, . Outcomes of a partnered facilitation strategy to implement primary care-mental health. Journal of General Internal Medicine. 2014;29 Suppl 4:904–12.25355087
37 Knierim KE, Hall TL, Dickinson LM, . Primary Care Practices’ Ability to Report Electronic Clinical Quality Measures in the EvidenceNOW Southwest Initiative to Improve Heart Health. JAMA Network Open. 2019;2(8).
38 Korner M, Becker S, Dinius J, . A patient-centred team-coaching concept for medical rehabilitation. Journal of Interprofessional Care. 2018;32(1):123–126.28972419
39 Lannon CM, Peterson LE. Pediatric collaborative networks for quality improvement and research. Academic Pediatrics. 2013;13(6 SUPPL.):S69–S74.24268088
40 Leamy M, Le Boutillier C, Bird V, . The REFOCUS randomised controlled trial: Lessons and early findings. Psychiatrische Praxis. 2011;38.
41 Leonard C, Lawrence E, McCreight M, . Implementation and dissemination of a transition of care program for rural veterans: a controlled before and after study. Implement Sci. 2017;12(1):123.29058640
42 Lindsay JA, Kauth MR, Hudson S, . Implementation of video telehealth to improve access to evidence-based psychotherapy for posttraumatic stress disorder. Telemedicine Journal & E-Health. 2015;21(6):467–72.25714664
43 McCormack RP, Hawk K, D’Onofrio G, . 159 Implementing Emergency Department-Initiated Buprenorphine in Low-Resource, High-Need Settings. Annals of Emergency Medicine. 2019;74(4):S62–S63.31655681
44 McNally K, Lukens R. Leadership development: an external-internal coaching partnership. Journal of Nursing Administration. 2006;36(3):155–61.
45 Meurer WJ, Majersik JJ, Frederiksen SM, . Provider perceptions of barriers to the emergency use of tPA for acute ischemic stroke: a qualitative study. BMC Emergency Medicine. 2011;11(1):5–5.21548943
46 Michaels L, Anastas T, Waddell EN, . A Randomized Trial of High-Value Change Using Practice Facilitation. Journal of the American Board of Family Medicine: JABFM. 2017;30(5):572–582.28923809
47 Midboe AM, Martino S, Krein SL, . Testing implementation facilitation of a primary care-based collaborative care clinical program using a hybrid type III interrupted time series design: a study protocol. Implement Sci. 2018;13(1):145.30486877
48 Modell M, Wonke B, Anionwu E, . A multidisciplinary approach for improving services in primary care: randomised controlled trial of screening for haemoglobin disorders. BMJ. 1998;317(7161):788–91.9740569
49 Mullen JE, Kelloway EK. Safety leadership: a longitudinal study of the effects of transformational leadership on safety outcomes. Journal of Occupational & Organizational Psychology. 2009;82(2):253–272.
50 Naccarella L, Butterworth I, Moore T. Transforming Health Professionals into Population Health Change Agents. Journal of Public Health Research. 2016;5(1):643.27190973
51 Nagykaldi Z, Mold JW, Aspy CB. Practice facilitators: a review of the literature. Fam Med. 2005;37(8):581–8.16145629
52 Nowalk MP, Lin CJ, Pavlik VN, . Using the 4 PillarsTM Practice Transformation Program to increase adult Tdap immunization in a randomized controlled cluster trial. Vaccine. 2016;34(41):5026–5033.27576073
53 Parchman ML, Anderson ML, Dorr DA, . A Randomized Trial of External Practice Support to Improve Cardiovascular Risk Factors in Primary Care. Ann Fam Med. 2019;17(Suppl 1):S40–S49.31405875
54 Parchman ML, Pugh JA, Culler SD, . A group randomized trial of a complexity-based organizational intervention to improve risk factors for diabetes complications in primary care settings: study protocol. Implement Sci. 2008;3:15.18321386
55 Pearlman DN, Camberg L, Wallace LJ, . Tapping youth as agents for change: evaluation of a peer leadership HIV/AIDS intervention. Journal of Adolescent Health. 2002;31(1):31–9.
56 Persson LA, Nga NT, Malqvist M, . Effect of Facilitation of Local Maternal-and-Newborn Stakeholder Groups on Neonatal Mortality: Cluster-Randomized Controlled Trial. PLoS Medicine / Public Library of Science. 2013;10(5):e1001445.
57 Petro-Nustas W. Evaluation of the process of introducing a quality development program in a nursing department at a teaching hospital: the role of a change agent. International Journal of Nursing Studies. 1996;33(6):605–18.8970858
58 Rakhmanova NA, Snidevich U, Semenenko I. Improving HIV service delivery in detention centers and ART facility in Odessa, Ukraine. International Journal of Infectious Diseases. 2016;45:162.
59 Rantz MJ, Popejoy L, Vogelsmeier A, . Successfully Reducing Hospitalizations of Nursing Home Residents: Results of the Missouri Quality Initiative. Journal of the American Medical Directors Association. 2017;18(11):960–966.28757334
60 Roderick SS, Burdette N, Hurwitz D, . Integrated behavioral health practice facilitation in patient centered medical homes: A promising application. Families, Systems, & Health. 2017;35(2):227–237.
61 Ruhe MC, Weyer SM, Zronek S, . Facilitating practice change: lessons from the STEP-UP clinical trial. Preventive Medicine. 2005;40(6):729–34.15850872
62 Salbach NM, Wood-Dauphinee S, Barreca S, . Contributing evidence of the effectiveness of an active, multi-component knowledge translation intervention in improving implementation of a stroke rehabilitation guideline: Results from the stroke Canada optimization of rehabilitation through evidence-implementation trial (score-it). Stroke. 2014;45(12):e266.
63 Sarin E, Livesley N. Quality Improvement Approaches Associated with Quality of Childbirth Care Practices in Six Indian States. Indian Pediatrics. 2018;55(9):789–792.30345987
64 Schiff GD, Reyes Nieva H, Griswold P, . Randomized Trial of Reducing Ambulatory Malpractice and Safety Risk: Results of the Massachusetts PROMISES Project. Medical Care. 2017;55(8):797–805.28650922
65 Schmidt I, Claesson CB, Westerholm B, . The impact of regular multidisciplinary team interventions on psychotropic prescribing in Swedish nursing homes. J Am Geriatr Soc. 1998;46(1):77–82.9434669
66 Siman N, Cleland C, Berry C, . The impact of practice facilitation on adherence to cardiovascular disease prevention guidelines. Circulation. 2018;138.
67 Smith SN, Almirall D, Prenovost K, . Change in Patient Outcomes After Augmenting a Low-level Implementation Strategy in Community Practices That Are Slow to Adopt a Collaborative Chronic Care Model: A Cluster Randomized Implementation Trial. Medical Care. 2019;57(7):503–511.31135692
68 Solberg LI, Kottke TE, Brekke ML. Will primary care clinics organize themselves to improve the delivery of preventive services? A randomized controlled trial. Prev Med. 1998;27(4):623–31.9672958
69 Starkey M, Wiest D, Qaseem A. Improving Depression Care Through an Online Learning Collaborative. American Journal of Medical Quality. 2016;31(2):111–7.25351473
70 Steiner RM, Walsworth DT. Using quality experts from manufacturing to transform primary care. Journal of Continuing Education in the Health Professions. 2010;30(2):95–105.
71 Thom DH, Wolf J, Gardner H, . A Qualitative Study of How Health Coaches Support Patients in Making Health-Related Decisions and Behavioral Changes. Ann Fam Med. 2016;14(6):509–516.28376437
72 Trott MC, Windsor K. Leadership effectiveness: how do you measure up? Nursing Economic$. 1999;17(3):127–130.
73 Verreault R, Arcand M, Misson L, . Quasi-experimental evaluation of a multifaceted intervention to improve quality of end-of-life care and quality of dying for patients with advanced dementia in long-term care institutions. Palliative Medicine. 2018;32(3):613–621.28731379
74 Vos L, Duckers ML, Wagner C, . Applying the quality improvement collaborative method to process redesign: a multiple case study. Implement Sci. 2010;5:19.20184762
75 Wray LO, Ritchie MJ, Oslin DW, . Enhancing implementation of measurement-based mental health care in primary care: a mixed-methods randomized effectiveness evaluation of implementation facilitation. BMC Health Serv Res. 2018;18(1):753.30285718
76 Zimmerman RK, Brown AE, Pavlik VN, . Using the 4 Pillars Practice Transformation Program to Increase Pneumococcal Immunizations for Older Adults: A Cluster-Randomized Trial. Journal of the American Geriatrics Society. 2017;65(1):114–122.27755655

## KEY QUESTION 2

Exclusion Reason

Study | Not OECD country | Not eligible evaluation | Not eligible sample | Not phenomenon of interest | Not eligible design | Not eligible research type
Ali, 2014^1^ | | ✕
Ammentorp, 2010^2^ | | ✕
Andersen, 2015^3^ | | ✕
Asselin, 2017^4^ | | ✕
Baskerville, 2001^5^ | | | | | ✕
Bauer, 2019^6^ | | ✕
Bauer, 2016^7^ | | ✕
Bender, 2011^8^ | | ✕
Bennell, 2017^9^ | | ✕
Boamah, 2018^10^ | | ✕
Bradd, 2018^11^ | | | | ✕
Bridges, 2013^12^ | | ✕
Brooker, 2016^13^ | | ✕
Brouwers, 2016^14^ | | ✕
Brunette, 2008^15^ | | ✕
Budhoo, 2011^16^ | | ✕
Cable, 2018^17^ | | | ✕
Calo, 2019^18^ | | | | ✕
Campbell, 2012^19^ | | ✕
Chan, 2010^20^ | | ✕
Chreim, 2010^21^ | | | | ✕
Chuang, 2014^22^ | | ✕
Cicirello, 2005^23^ | | ✕
Cranley, 2017^24^ | | | | | ✕
Cummings, 2014^25^ | | | | ✕
Devers, 2013^26^ | | ✕
Dickinson, 2014^27^ | | ✕
Dietrich, 1992^28^ | | ✕
Dimas, 2016^29^ | | ✕
Dobbins, 2019^30^ | | ✕
Donahue, 2013^31^ | | ✕
Donaldson, 2008^32^ | | | ✕
du Toit, 2019^33^ | | | | ✕
Duff, 2013^34^ | | ✕
Echevarria, 2016^35^ | | ✕
Edwards, 2018^36^ | | ✕
Eiff, 2016^37^ | | ✕
Fearing, 2014^38^ | | | | ✕
Felder, 2017^39^ | | ✕
Fernald, 2019^40^ | | ✕
Fernald, 2013^41^ | | ✕
Fox, 2013^42^ | | ✕
Gandhi, 2000^43^ | | ✕
Gannon, 2011^44^ | | ✕
Garbutt, 2018^45^ | | ✕
Garrard, 2006^46^ | | | | ✕
Gastala, 2018^47^ | | ✕
George, 2015^48^ | ✕
Gingold,2016^49^ | | ✕
Gold, 2015^50^ | | ✕
Gonzalo, 2019^51^ | | ✕
Gordon, 2013^52^ | | ✕
Grandes, 2017^53^ | | ✕
Grant, 2017^54^ | | ✕
Greenberg, 2018^55^ | | | ✕
Greiver, 2019^56^ | | | | ✕
Hackshaw, 2016^57^ | | | ✕
Hall, 2019^58^ | | ✕
Halladay, 2016^59^ | | ✕
Halladay, 2017^60^ | | ✕
HallebergNyman,2019^61^ | | ✕
Hallett, 1997^62^ | | ✕
Harris, 2018^63^ | | ✕
Harvey, 2012^64^ | | | | ✕
Harvey, 2018^65^ | | | ✕
Hill, 2015^66^ | | ✕
Hill, 2015^67^ | | ✕
Hogg, 2008^68^ | | ✕
Hogg, 2008^69^ | | | | | ✕
Homa, 2008^70^ | | ✕
Houle, 2017^71^ | | ✕
Huguet, 2018^72^ | | ✕
Iyasere, 2016^73^ | | | ✕
Jansen, 2008^74^ | | ✕
Jefferies, 2012^75^ | | ✕
Jinks, 2009^76^ | | ✕
Johnson, 2011^77^ | | | ✕
Johnson, 2014^78^ | | ✕
Jones, 1992^79^ | | ✕
Jortberg, 2014^80^ | | ✕
Kaplan, 2013^81^ | | ✕
Katz, 2014^82^ | | ✕
Kavanagh,2010^83^ | | ✕
Kjaerbeck, 2014^84^ | | ✕
Klop, 2017^85^ | | ✕
Korner, 2018^86^ | | | | ✕
Kotecha, 2015^87^ | | ✕
Lazorick, 2008^88^ | | ✕
Lefebvre, 2019^89^ | | ✕
Liddy, 2017^90^ | | ✕
Liddy, 2018^91^ | | ✕
Lipman,2016^92^ | | ✕
Loeb, 2019^93^ | | ✕
Luig,2018^94^ | | ✕
Mader, 2016^95^ | | ✕
Madsen, 2016^96^ | | | | ✕
Mahloch, 1993^97^ | | ✕
Malik, 2016^98^ | | ✕
McCullough, 2017^99^ | | | ✕
McGloin,2015^100^ | | ✕
McIntosh, 2009^101^ | | ✕
McNamara, 2014^102^ | | ✕
Meurer, 2011^103^ | | ✕
Mignogna, 2014^104^ | | | | | ✕
Miller, 2018^105^ | | ✕
Mold, 2008^106^ | | ✕
Moriarty, 2007^107^ | | ✕
Morley, 2018^108^ | | ✕
Mulcahy, 2018^109^ | | ✕
Mutabdzic, 2015^110^ | | ✕
Naik, 2015^111^ | | ✕
Nease, 2008^112^ | | ✕
Noel, 2013^113^ | | ✕
O’Malley, 1992^114^ | | ✕
Owen, 2013^115^ | | ✕
Palmer, 2019^116^ | | ✕
Pandhi, 2019^117^ | | ✕
Paquette-Warren, 2014^118^ | | ✕
Parchman, 2016^119^ | | ✕
Parchman, 2013^120^ | | ✕
Pérez-Escamilla, 2014^121^ | | ✕
Piers, 2017^122^ | | ✕
Pimentel, 2019^123^ | | ✕
Ploeg,2010^124^ | | | ✕
Pollak, 2016^125^ | | ✕
Prenkert, 1997^126^ | | ✕
Rafferty, 2015^127^ | | ✕
Richters, 2018^128^ | | ✕
Ritchie, 2017^129^ | | ✕
Rivers, 2011^13^ ° | | ✕
Rodenbach, 2019^131^ | | ✕
Salsbury, 2018^132^ | | ✕
Sathe, 2013^133^ | | ✕
Schiff, 2017^134^ | | ✕
Schiff, 2017^135^ | | ✕
Shunk, 2014^136^ | | | | ✕
Starkey, 2016^137^ | | ✕
Stetler, 2006^138^ | | ✕
Stover, 2014^139^ | ✕
Tabak, 2018^140^ | | ✕
Tafvelin, 2014^141^ | | ✕
Tatla, 2017^142^ | | ✕
Thomas, 2014^143^ | | ✕
van Berkel, 2019^144^ | | | ✕
van Dongen, 2018^145^ | | | | ✕
Volker, 2017^146^ | | ✕
Waldrop, 2019^147^ | | | ✕
Watts, 2014^148^ | | ✕
Weiner, 2017^149^ | | ✕
Weng,2015^150^ | | ✕
Westcott, 2016^151^ | | | ✕
Wilkie, 1995^152^ | | ✕
Woloschuk, 2012^153^ | | ✕
Wray, 2018^154^ | | ✕
Young, 2007^155^ | | ✕

### References for KQ 2 Excluded Studies

1 Ali KJ, Farley DO, Speck K, . Measurement of implementation components and contextual factors in a two-state healthcare quality initiative to reduce ventilator-associated pneumonia. Infection Control and Hospital Epidemiology. 2014;35:S116–S123.25222890
2 Ammentorp J, Kofoed PE. Coach training can improve the self-efficacy of neonatal nurses. A pilot study. Patient Education & Counseling. 2010;79(2):258–61.
3 Andersen H, Rovik KA. Lost in translation: a case-study of the travel of lean thinking in a hospital. BMC Health Serv Res. 2015;15:401.26390900
4 Asselin J, Salami E, Osunlana AM, . Impact of the 5As Team study on clinical practice in primary care obesity management: a qualitative study. CMAJ open. 2017;5(2):E322–E329.
5 Baskerville NB, Hogg W, Lemelin J. Process evaluation of a tailored multifaceted approach to changing family physician practice patterns improving preventive care. Journal of Family Practice. 2001;50(3):W242–9.
6 Bauer MS, Miller CJ, Kim B, . Effectiveness of Implementing a Collaborative Chronic Care Model for Clinician Teams on Patient Outcomes and Health Status in Mental Health: A Randomized Clinical Trial. JAMA Network Open. 2019;2(3):e190230.30821830
7 Bauer MS, Miller C, Kim B, . Partnering with health system operations leadership to develop a controlled implementation trial. Implement Sci. 2016;11:22.26912342
8 Bender BG, Dickinson P, Rankin A, . The Colorado Asthma Toolkit Program: a practice coaching intervention from the High Plains Research Network. Journal of the American Board of Family Medicine: JABFM. 2011;24(3):240–8.21551395
9 Bennell KL, Campbell PK, Egerton T, . Telephone Coaching to Enhance a Home-Based Physical Activity Program for Knee Osteoarthritis: A Randomized Clinical Trial. Arthritis Care and Research. 2017;69(1):84–94.27111441
10 Boamah SA, Spence Laschinger HK, Wong C, . Effect of transformational leadership on job satisfaction and patient safety outcomes. Nursing Outlook. 2018;66(2):180–189.29174629
11 Bradd P, Travaglia J, Hayen A. Developing allied health leaders to enhance person-centred healthcare. Journal of Health Organization & Management. 2018;32(7):908–932.30465488
12 Bridges RA, Holden-Huchton P, Armstrong ML. Transition to Nursing Practice of Accelerated Second-Degree Baccalaureate Students Using Clinical Coaches. Journal of Continuing Education in Nursing. 2013;44(5):225–229.23458079
13 Brooker DJ, Latham I, Evans SC, . FITS into practice: translating research into practice in reducing the use of anti-psychotic medication for people with dementia living in care homes. Aging & mental health. 2016;20(7):709–718.26167720
14 Brouwers MC, Vukmirovic M, Tomasone JR, . Documenting coordination of cancer care between primary care providers and oncology specialists in Canada. Canadian Family Physician. 2016;62(10):e616–e625.27737997
15 Brunette MF, Asher D, Whitley R, . Implementation of integrated dual disorders treatment: a qualitative analysis of facilitators and barriers. Psychiatric Services. 2008;59(9):989–95.18757591
16 Budhoo MR, Spurgeon P. Views and understanding of clinicians on the leadership role and attitude to coaching as a development tool for clinical leadership. International Journal of Clinical Leadership. 2011;17(3–4):123–129.
17 Cable S, Graham E. “Leading Better Care”: An evaluation of an accelerated coaching intervention for clinical nursing leadership development. J Nurs Manag. 2018;26(5):605–612.29600826
18 Calo WA, Gilkey MB, Leeman J, . Coaching primary care clinics for HPV vaccination quality improvement: Comparing in-person and webinar implementation. Translational Behavioral Medicine. 2019;9(1):23–31.29471460
19 Campbell TD. Clinical Nurse Specialists’ Role in Promoting Evidence Based Practice in Saskatchewan’s Health Care Settings. University of Alberta (Canada); 2012.
20 Chan BC, Perkins D, Wan Q, . Finding common ground? Evaluating an intervention to improve teamwork among primary health-care professionals. International Journal for Quality in Health Care. 2010;22(6):519–524.20956284
21 Chreim S, Williams BE, Janz L, . Change agency in a primary health care context: the case of distributed leadership. Health Care Management Review. 2010;35(2):187–99.20234224
22 Chuang E, Ganti V, Alvi A, . Implementing panel management for hypertension in a low-income, urban, primary care setting. Journal of Primary Care & Community Health. 2014;5(1):61–6.
23 Cicirello NA. The role of parent coaching by pediatric physical therapists: An exploration of current practice. Portland State University; 2005.
24 Cranley LA, Cummings GG, Profetto-McGrath J, . Facilitation roles and characteristics associated with research use by healthcare professionals: a scoping review. BMJ Open. 2017;7(8):e014384.
25 Cummings G, Mallidou AA, Masaoud E, . On becoming a coach: a pilot intervention study with managers in long-term care. Health Care Management Review. 2014;39(3):198–209.23624830
26 Devers KJ, Foster L, Brach C. Nine states’ use of collaboratives to improve children’s health care quality in medicaid and CHIP. Academic pediatrics. 2013;13(6 Suppl):S95–102.24268093
27 Dickinson WP, Dickinson LM, Nutting PA, . Practice facilitation to improve diabetes care in primary care: a report from the EPIC randomized clinical trial. Ann Fam Med. 2014;12(1):8–16.24445098
28 Dietrich AJ, O’Connor GT, Keller A, . Cancer: improving early detection and prevention. A community practice randomised trial. BMJ. 1992;304(6828):687–91.
29 Dimas ID, Renato Lourenco P, Rebelo T. The effects on team emotions and team effectiveness of coaching in interprofessional health and social care teams. Journal of Interprofessional Care. 2016;30(4):416–22.27135137
30 Dobbins M, Greco L, Yost J, . A description of a tailored knowledge translation intervention delivered by knowledge brokers within public health departments in Canada. Health Research Policy & Systems. 2019;17(1):63.31221187
31 Donahue KE, Halladay JR, Wise A, . Facilitators of transforming primary care: a look under the hood at practice leadership. Ann Fam Med. 2013;11 Suppl 1:S27–33.23690383
32 Donaldson N, Rutledge D, Geiser K. Role of the External Coach in Advancing Research Translation in Hospital-Based: Performance Improvement. Agency for Healthcare Research and Quality. 2008;08:08.
33 du Toit SHJ, Chan YL, Jessup GM, . Peer-enabled staff training in residential care settings as means for promoting person-centred dementia care. Aging & Mental Health. 2019:1–10.
34 Duff J, Walker K, Omari A, . Educational outreach visits to improve nurses’ use of mechanical venous thromboembolism prevention in hospitalized medical patients. Journal of Vascular Nursing. 2013;31(4):139–49.24238096
35 Echevarria M. Translating Knowledge Into Practice Through an Academic-Practice Partnership for Exploring Barriers That Impact Management of Homebound Patients With Heart Failure. Care Management Journals. 2016;17(2):81–96.27298135
36 Edwards NC, Smith Higuchi K. Process Evaluation of a Participatory, Multimodal Intervention to Improve Evidence-Based Care in Long-Term Care Settings. Worldviews on Evidence-Based Nursing. 2018;15(5):361–367.30022601
37 Eiff MP, Green LA, Holmboe E, . A Model for Catalyzing Educational and Clinical Transformation in Primary Care: Outcomes From a Partnership Among Family Medicine, Internal Medicine, and Pediatrics. Academic Medicine. 2016;91(9):1293–304.27028034
38 Fearing G, Barwick M, Kimber M. Clinical transformation: Manager’s perspectives on implementation of evidence-based practice. Administration & Policy in Mental Health. 2014;41(4):455–68.23494388
39 Felder JN, Segal Z, Beck A, . An Open Trial of Web-Based Mindfulness-Based Cognitive Therapy for Perinatal Women at Risk for Depressive Relapse. Cognitive and Behavioral Practice. 2017;24(1):26–37.
40 Fernald D, Hall T, Montgomery L, . Colorado Residency PCMH Project: Results From a 6-Year Transformation Effort. Fam Med. 2019;51(7):578–586.31125420
41 Fernald DH, Wearner R, Dickinson WP. The journey of primary care practices to meaningful use: a colorado beacon consortium study. J Am Board Fam Med. 2013;26(5):603–611.24004712
42 Fox CH, Vest BM, Kahn LS, . Improving evidence-based primary care for chronic kidney disease: study protocol for a cluster randomized control trial for translating evidence into practice (TRANSLATE CKD). Implement Sci. 2013;8:88.23927603
43 Gandhi TK, Puopolo AL, Dasse P, . Obstacles to collaborative quality improvement: the case of ambulatory general medical care. International Journal for Quality in Health Care. 2000;12(2):115–23.10830668
44 Gannon M, Qaseem A, Snow V, . Using online learning collaboratives to facilitate practice improvement for COPD: an ACPNet pilot study. American Journal of Medical Quality. 2011;26(3):212–9.21266597
45 Garbutt JM, Dodd S, Walling E, . Theory-based development of an implementation intervention to increase HPV vaccination in pediatric primary care practices. Implement Sci. 2018;13(1):45.29534761
46 Garrard J, Choudary V, Groom H, . Organizational change in management of hepatitis C: evaluation of a CME program. Journal of Continuing Education in the Health Professions. 2006;26(2):145–60.
47 Gastala NM, Wingrove PM, Gaglioti AH, . The Growing Trend of Health Coaches in Team-Based Primary Care Training A Multicenter Pilot Study. Fam Med. 2018;50(7):526–530.30005115
48 George A, Blankenship KM, Biradavolu MR, . Sex workers in HIV prevention: From Social Change Agents to Peer Educators. Global Public Health. 2015;10(1):28–40.25359518
49 Gingold JA, Briccetti C, Zook K, . Context Matters: Practitioner Perspectives on Immunization Delivery Quality Improvement Efforts. Clinical Pediatrics. 2016;55(9):825–37.26743455
50 Gold R, Hollombe C, Bunce A, . Study protocol for “Study of Practices Enabling Implementation and Adaptation in the Safety Net (SPREAD-NET)”: a pragmatic trial comparing implementation strategies. Implement Sci. 2015;10:144.26474759
51 Gonzalo JD, Wolpaw DR, Krok KL, . A Developmental Approach to Internal Medicine Residency Education: Lessons Learned from the Design and Implementation of a Novel Longitudinal Coaching Program. Medical education online. 2019;24(1):1591256.30924404
52 Gordon SJ, Melillo KD, Nannini A, . Bedside coaching to improve nurses’ recognition of delirium. Journal of Neuroscience Nursing. 2013;45(5):288–293.
53 Grandes G, Sanchez A, Cortada JM, . Collaborative modeling of an implementation strategy: a case study to integrate health promotion in primary and community care. BMC Research Notes. 2017;10(1):699.29208052
54 Grant AM, Studholme I, Verma R, . The impact of leadership coaching in an Australian healthcare setting. Journal of health organization and management. 2017;31(2):237–252.28482767
55 Greenberg CC, Ghousseini HN, Pavuluri Quamme SR, . A Statewide Surgical Coaching Program Provides Opportunity for Continuous Professional Development. Annals of Surgery. 2018;267(5):868–873.28650360
56 Greiver M, Dahrouge S, O’Brien P, . Improving care for elderly patients living with polypharmacy: protocol for a pragmatic cluster randomized trial in community-based primary care practices in Canada. Implement Sci. 2019;14(1):55.31171011
57 Hackshaw KV, Plans-Pujolras M, Rodriguez-Saona LE, . A pilot study of health and wellness coaching for fibromyalgia. BMC Musculoskeletal Disorders. 2016;17(1):457.27821160
58 Hall TL, Knierim KE, Nease DE, Jr., . Primary Care Practices’ Implementation of Patient-Team Partnership: Findings from EvidenceNOW Southwest. Journal of the American Board of Family Medicine: JABFM. 2019;32(4):490–504.31300569
59 Halladay JR, Mottus K, Reiter K, . The Cost to Successfully Apply for Level 3 Medical Home Recognition. Journal of the American Board of Family Medicine: JABFM. 2016;29(1):69–77.26769879
60 Halladay JR, Tillman J, Hinderliter A, . Practice level costs of office-based hypertension performance improvement: The Heart Healthy Lenoir study. Journal of Healthcare Management. 2017;62(2):136–150.28282337
61 Hälleberg Nyman M, Forsman H, Wallin L, . Promoting evidence‐based urinary incontinence management in acute nursing and rehabilitation care—A process evaluation of an implementation intervention in the orthopaedic context. Journal of Evaluation in Clinical Practice. 2019;25(2):282–289.29411463
62 Hallett CE. Learning through reflection in the community: the relevance of Schon’s theories of coaching to nursing education. International Journal of Nursing Studies. 1997;34(2):103–10.9134465
63 Harris M, Bonnington O, Harrison G, . Understanding hepatitis C intervention success-Qualitative findings from the HepCATT study. Journal of Viral Hepatitis. 2018;25(7):762–770.29369467
64 Harvey G, Kitson A, Munn Z. Promoting continence in nursing homes in four European countries: the use of PACES as a mechanism for improving the uptake of evidence-based recommendations. International Journal of Evidence-Based Healthcare. 2012;10(4):388–96.23173664
65 Harvey G, McCormack B, Kitson A, . Designing and implementing two facilitation interventions within the ‘Facilitating Implementation of Research Evidence (FIRE)’ study: a qualitative analysis from an external facilitators’ perspective. Implement Sci. 2018;13(1):141.30442157
66 Hill JN, Smith BM, Evans CT, . Implementing a declination form programme to improve influenza vaccine uptake by staff in Department of Veterans Affairs spinal cord injury centres: a pilot study. Journal of Hospital Infection. 2015;91(2):158–65.
67 Hill JN, Suda KJ, Ramanathan S, . Development of a unit-specific antibiogram and planning for implementation: Preimplementation findings. American Journal of Infection Control. 2015;43(11):1264–1267.26283492
68 Hogg W, Lemelin J, Graham ID, . Improving prevention in primary care: evaluating the effectiveness of outreach facilitation. Fam Pract. 2008;25(1):40–8.18209107
69 Hogg W, Lemelin J, Moroz I, . Improving prevention in primary care: Evaluating the sustainability of outreach facilitation. Canadian Family Physician. 2008;54(5):712–20.18474705
70 Homa K, Regan-Smith M, Foster T, . Coaching physicians in training to lead improvement in clinical microsystems: a qualitative study on the role of the clinical coach. International Journal of Clinical Leadership. 2008;16(1):37–48.
71 Houle SK, Charrois TL, Faruquee CF, . A randomized controlled study of practice facilitation to improve the provision of medication management services in Alberta community pharmacies. Research In Social & Administrative Pharmacy. 2017;13(2):339–348.27017157
72 Huguet N, Hatch B, Sumic A, . Implementation of Health Insurance Support Tools in Community Health Centers. Journal of the American Board of Family Medicine: JABFM. 2018;31(3):410–416.29743224
73 Iyasere CA, Baggett M, Romano J, . Beyond Continuing Medical Education: Clinical Coaching as a Tool for Ongoing Professional Development. Academic Medicine. 2016;91(12):1647–1650.26910898
74 Jansen M, Harting J, Ebben N, . The concept of sustainability and the use of outcome indicators. A case study to continue a successful health counselling intervention. Fam Pract. 2008;25 Suppl 1:i32–7.
75 Jefferies D, Johnson M, Nicholls D, . Evaluating an intensive ward-based writing coach programme to improve nursing documentation: lessons learned. International Nursing Review. 2012;59(3):394–401.22897192
76 Jinks AM, Armitage H, Pitt R. A qualitative evaluation of an interprofessional learning project. Learning in Health & Social Care. 2009;8(4):263–271.
77 Johnson A, Hong H, Groth M, . Learning and development: promoting nurses’ performance and work attitudes. J Adv Nurs. 2011;67(3):609–20.20969619
78 Johnson KE, Coleman K, Phillips KE, . Development of a facilitation curriculum to support primary care transformation: the “coach medical home” curriculum. Medical Care. 2014;52(11 Suppl 4):S26–32.25310635
79 Jones JN, Marsden P. Improved diabetes care in a UK health district. Diabetic Medicine. 1992;9(2):176–80.1563253
80 Jortberg BT, Fernald DH, Dickinson LM, . Curriculum redesign for teaching the PCMH in Colorado Family Medicine Residency programs. Fam Med. 2014;46(1):11–8.24415503
81 Kaplan HC, Froehle CM, Cassedy A, . An exploratory analysis of the Model for Understanding Success in Quality. Health Care Management Review. 2013;38(4):325–338.22914176
82 Katz DA, Holman JE, Johnson SR, . Implementing Best Evidence in Smoking Cessation Treatment for Hospitalized Veterans: Results from the VA-BEST Trial. Joint Commission Journal on Quality & Patient Safety. 2014;40(11):493–1.26111367
83 Kavanagh PM. Appreciative Inquiry: An interactive organizational intervention to translate acute pain management evidence into pediatric nursing practice. University of Toronto (Canada); 2010.
84 Kjaerbeck S, Petersen H. [Hygiene communication - conditions for change]. Ugeskrift for Laeger. 2014;176(23):02.
85 Klop R, Klompmaker L. Evaluation of knowledge vouchers as instrument for implementing good practices. International Journal of Integrated Care (IJIC). 2017;17:1–2.
86 Korner M, Becker S, Dinius J, . A patient-centred team-coaching concept for medical rehabilitation. Journal of Interprofessional Care. 2018;32(1):123–126.28972419
87 Kotecha J, Brown JB, Han H, . Influence of a quality improvement learning collaborative program on team functioning in primary healthcare. Families, Systems, & Health. 2015;33(3):222–30.
88 Lazorick S, Crowe VL, Dolins JC, . Structured intervention utilizing state professional societies to foster quality improvement in practice. Journal of Continuing Education in the Health Professions. 2008;28(3):131–9.
89 Lefebvre G, Honey L, Hines K, . Implementing Obstetrics Quality Improvement, Driven by Medico-legal Risk, is Associated With Improved Workplace Culture. Journal of Obstetrics and Gynaecology Canada. 2019.
90 Liddy C, Rowan M, Valiquette-Tessier SC, . Improved Delivery of Cardiovascular Care (IDOCC): Findings from Narrative Reports by Practice Facilitators. Preventive Medicine Reports. 2017;5:214–219.28271017
91 Liddy C, Rowan M, Valiquette-Tessier SC, . Experiences of practice facilitators working on the Improved Delivery of Cardiovascular Care project: Retrospective case study. Canadian Family Physician. 2018;64(1):e23–e32.29358265
92 Lipman PD, Aspy CB. Local Learning Collaboratives to Improve Quality for Chronic Kidney Disease (CKD): From Four Regional Practice-based Research Networks (PBRNs). Journal of the American Board of Family Medicine: JABFM. 2016;29(5):543–52.27613787
93 Loeb DF, Kline DM, Kroenke K, . Designing the relational team development intervention to improve management of mental health in primary care using iterative stakeholder engagement. BMC Fam Pract. 2019;20(1):124.31492096
94 Luig T, Asselin J, Sharma AM, . Understanding Implementation of Complex Interventions in Primary Care Teams. Journal of the American Board of Family Medicine: JABFM. 2018;31(3):431–444.29743226
95 Mader EM, Fox CH, Epling JW, . A Practice Facilitation and Academic Detailing Intervention Can Improve Cancer Screening Rates in Primary Care Safety Net Clinics. Journal of the American Board of Family Medicine: JABFM. 2016;29(5):533–42.27613786
96 Madsen WC. Narrative Approaches to Organizational Development: A Case Study of Implementation of Collaborative Helping. Family Process. 2016;55(2):253–69.27080245
97 Mahloch J, Taylor V, Taplin S, . A breast cancer screening educational intervention targeting medical office staff. Health Education Research. 1993;8(4):567–79.10146564
98 Malik G, McKenna L, Plummer V. Facilitators and barriers to evidence-based practice: perceptions of nurse educators, clinical coaches and nurse specialists from a descriptive study. Contemporary Nurse. 2016;52(5):544–554.27160348
99 McCullough MB, Gillespie C, Petrakis BA, . Forming and activating an internal facilitation group for successful implementation: A qualitative study. Research In Social & Administrative Pharmacy. 2017;13(5):1014–1027.28434918
100 McGloin H, Timmins F, Coates V, . A case study approach to the examination of a telephone-based health coaching intervention in facilitating behaviour change for adults with Type 2 diabetes. Journal of Clinical Nursing. 2015;24(9–10):1246–57.25319572
101 McIntosh J, Tolson D. Leadership as part of the nurse consultant role: banging the drum for patient care. Journal of Clinical Nursing. 2009;18(2):219–27.19120750
102 McNamara MS, Fealy GM, Casey M, . Mentoring, coaching and action learning: interventions in a national clinical leadership development programme. Journal of clinical nursing. 2014;23(17–18):2533–2541.24393275
103 Meurer WJ, Majersik JJ, Frederiksen SM, . Provider perceptions of barriers to the emergency use of tPA for acute ischemic stroke: a qualitative study. BMC Emergency Medicine. 2011;11(1):5–5.21548943
104 Mignogna J, Hundt NE, Kauth MR, . Implementing brief cognitive behavioral therapy in primary care: A pilot study. Translational Behavioral Medicine. 2014;4(2):175–83.24904701
105 Miller R, Weir C, Gulati S. Transforming primary care: scoping review of research and practice. Journal of Integrated Care. 2018;26(3):176–188.30166943
106 Mold JW, Aspy CA, Nagykaldi Z, . Implementation of evidence-based preventive services delivery processes in primary care: an Oklahoma Physicians Resource/Research Network (OKPRN) study. Journal of the American Board of Family Medicine: JABFM. 2008;21(4):334–44.18612060
107 Moriarty D, O’Hara A, Byron S. Macmillan nurse facilitators for palliative care: evaluation of a pilot project. International Journal of Palliative Nursing. 2007;13(7):334–43.17851377
108 Morley KE, Barysauskas CM, Carballo V, . Characteristics of Volunteer Coaches in a Clinical Process Improvement Program. Quality Management in Health Care. 2018;27(2):81–86.29596268
109 Mulcahy M, Lowry C, Hoban K, . Perspectives and experiences of nurses as facilitators within a Practice Development program. Collegian. 2018;25(1):3–10.
110 Mutabdzic D, Mylopoulos M, Murnaghan ML, . Coaching surgeons: Is culture limiting our ability to improve? Annals of Surgery. 2015;262(2):213–216.25894418
111 Naik AD, Lawrence B, Kiefer L, . Building a primary care/research partnership: lessons learned from a telehealth intervention for diabetes and depression. Fam Pract. 2015;32(2):216–223.25552674
112 Nease DE, Jr., Nutting PA, Dickinson WP, . Inducing sustainable improvement in depression care in primary care practices. Joint Commission Journal on Quality & Patient Safety. 2008;34(5):247–55.18491688
113 Noel PH, Lanham HJ, Palmer RF, . The importance of relational coordination and reciprocal learning for chronic illness care within primary care teams. Health Care Management Review. 2013;38(1):20–8.22310483
114 O’Malley J. Transformational leadership in action: an interview with a health care executive. Interview by Gloria E. Bader. Nursing Administration Quarterly. 1992;17(1):38–44.1436747
115 Owen RR, Drummond KL, Viverito KM, . Monitoring and managing metabolic effects of antipsychotics: a cluster randomized trial of an intervention combining evidence-based quality improvement and external facilitation. Implement Sci. 2013;8:120.24103648
116 Palmer JA, Parker VA, Mor V, . Barriers and facilitators to implementing a pragmatic trial to improve advance care planning in the nursing home setting. BMC Health Serv Res. 2019;19(1):527.31357993
117 Pandhi N, Jacobson N, Crowder M, . Engaging Patients in Primary Care Quality Improvement Initiatives: Facilitators and Barriers. American Journal of Medical Quality. 2019:1062860619842938.
118 Paquette-Warren J, Roberts SE, Fournie M, . Improving chronic care through continuing education of interprofessional primary healthcare teams: a process evaluation. Journal of Interprofessional Care. 2014;28(3):232–8.24397571
119 Parchman ML, Fagnan LJ, Dorr DA, . Study protocol for “Healthy Hearts Northwest”: a 2 × 2 randomized factorial trial to build quality improvement capacity in primary care. Implement Sci. 2016;11(1):138.27737719
120 Parchman ML, Noel PH, Culler SD, . A randomized trial of practice facilitation to improve the delivery of chronic illness care in primary care: initial and sustained effects. Implement Sci. 2013;8:93.23965255
121 Pérez-Escamilla B, García-Cárdenas V, Gastelurrutia MA, . Perception of Practice Change Facilitators on the professional future of this new job in community pharmacy. Pharmaceutical Care Espana. 2014;16(3):81–88.
122 Piers RD, Versluys KJJ, Devoghel J, . A Typology of Interprofessional Teamwork in Acute Geriatric Care: A Study in 55 units in Belgium. Journal of the American Geriatrics Society. 2017;65(9):2064–2070.28631275
123 Pimentel CB, Mills WL, Palmer JA, . Blended Facilitation as an Effective Implementation Strategy for Quality Improvement and Research in Nursing Homes. Journal of Nursing Care Quality. 2019;34(3):210–216.30480614
124 Ploeg J, Skelly J, Rowan M, . The role of nursing best practice champions in diffusing practice guidelines: a mixed methods study. Worldviews on Evidence-Based Nursing. 2010;7(4):238–51.20880009
125 Pollak KI, Nagy P, Bigger J, . Effect of teaching motivational interviewing via communication coaching on clinician and patient satisfaction in primary care and pediatric obesity-focused offices. Patient Education and Counseling. 2016;99(2):300–303.26320822
126 Prenkert F, Ehnfors M. A measure of organizational effectiveness in nursing management in relation to transactional and transformational leadership: a study in a Swedish county hospital. J Nurs Manag. 1997;5(5):279–87.9348842
127 Rafferty R, Fairbrother G. Factors influencing how senior nurses and midwives acquire and integrate coaching skills into routine practice: a grounded theory study. J Adv Nurs. 2015;71(6):1249–1259.25560968
128 Richters A, Nieuwboer M, Rikkert MO, . Longitudinal multiple case study on effectiveness of network-based dementia care towards more integration, quality of care, and collaboration in primary care. International Journal of Integrated Care (IJIC). 2018;18:1–3.
129 Ritchie MJ, Parker LE, Edlund CN, . Using implementation facilitation to foster clinical practice quality and adherence to evidence in challenged settings: a qualitative study. BMC Health Serv Res. 2017;17(1):294.28424052
130 Rivers R, Pesata V, Beasley M, . Transformational Leadership: Creating A Prosperity-Planning Coaching Model for RN Retention. Nurse Leader. 2011;9(5):48–51.
131 Rodenbach R, Kavalieratos D, Tamber A, . Coaching Palliative Care Conversations: Evaluating the Impact on Resident Preparedness and Goals-of-Care Conversations. Journal of palliative medicine. 2019.
132 Salsbury SA, Goertz CM, Vining RD, . Interdisciplinary Practice Models for Older Adults With Back Pain: A Qualitative Evaluation. Gerontologist. 2018;58(2):376–387.28082277
133 Sathe A, Flowers E, Mathur A, . A culturally specific health coaching program targeting cardiovascular disease risk in south asians: Rationale, design, and baseline data. Ethnicity and Disease. 2013;23(3):304–309.23914415
134 Schiff GD, Bearden T, Hunt LS, . Primary Care Collaboration to Improve Diagnosis and Screening for Colorectal Cancer. Joint Commission Journal on Quality & Patient Safety. 2017;43(7):338–350.28648219
135 Schiff GD, Reyes Nieva H, Griswold P, . Randomized Trial of Reducing Ambulatory Malpractice and Safety Risk: Results of the Massachusetts PROMISES Project. Medical Care. 2017;55(8):797–805.28650922
136 Shunk R, Dulay M, Chou CL, . Huddle-coaching: a dynamic intervention for trainees and staff to support team-based care. Academic Medicine. 2014;89(2):244–50.24362383
137 Starkey M, Wiest D, Qaseem A. Improving Depression Care Through an Online Learning Collaborative. American Journal of Medical Quality. 2016;31(2):111–7.25351473
138 Stetler CB, Legro MW, Rycroft-Malone J, . Role of “external facilitation” in implementation of research findings: a qualitative evaluation of facilitation experiences in the Veterans Health Administration. Implement Sci. 2006;1:23.17049080
139 Stover KE, Tesfaye S, Frew AH, . Building district-level capacity for continuous improvement in maternal and newborn health. Journal of Midwifery & Women’s Health. 2014;59 Suppl 1:S91–S100.
140 Tabak RG, Dsouza N, Schwarz CD, . A formative study to understand perspectives of families eligible for a pediatric obesity program: a qualitative study. BMC Public Health. 2018;18(1):586.29720138
141 Tafvelin S, Hyvönen U, Westerberg K. Transformational Leadership in the Social Work Context: The Importance of Leader Continuity and Co-Worker Support. British Journal of Social Work. 2014;44(4):886–904.
142 Tatla SK, Howard D, Antunes Silvestre A, . Implementing a collaborative coaching intervention for professionals providing care to children and their families: An exploratory study. Journal of Interprofessional Care. 2017;31(5):604–612.28922022
143 Thomas CL, Man M-S, O’Cathain A, . Effectiveness and cost-effectiveness of a telehealth intervention to support the management of long-term conditions: study protocol for two linked randomized controlled trials. Trials. 2014;15(1):36–36.24460845
144 van Berkel C, Almond P, Hughes C, . Retrospective observational study of the impact on emergency admission of telehealth at scale delivered in community care in Liverpool, UK. BMJ Open. 2019;9(7):e028981.
145 van Dongen JJJ, van Bokhoven MA, Goossens WNM, . Development of a Customizable Programme for Improving Interprofessional Team Meetings: An Action Research Approach. International Journal of Integrated Care [Electronic Resource]. 2018;18(1):8.
146 Volker N, Williams LT, Davey RC, . Implementation of cardiovascular disease prevention in primary health care: enhancing understanding using normalisation process theory. BMC Fam Pract. 2017;18(1):28.28235400
147 Waldrop J, Derouin A. The Coaching Experience of Advanced Practice Nurses in a National Leadership Program. Journal of Continuing Education in Nursing. 2019;50(4):170–175.30942891
148 Watts B, Lawrence RH, Singh S, . Implementation of quality improvement skills by primary care teams: case study of a large academic practice. Journal of Primary Care & Community Health. 2014;5(2):101–6.
149 Weiner BJ, Rohweder CL, Scott JE, . Using Practice Facilitation to Increase Rates of Colorectal Cancer Screening in Community Health Centers, North Carolina, 2012–2013: Feasibility, Facilitators, and Barriers. Preventing Chronic Disease. 2017;14:E66.28817791
150 Weng RH, Huang CY, Chen LM, . Exploring the impact of transformational leadership on nurse innovation behaviour: a cross-sectional study. J Nurs Manag. 2015;23(4):427–39.24033847
151 Westcott L. How coaching can play a key role in the development of nurse managers. Journal of Clinical Nursing. 2016;25(17–18):2669–77.27501254
152 Wilkie DJ, Williams AR, Grevstad P, . Coaching persons with lung cancer to report sensory pain: Literature review and pilot study findings. Cancer Nursing. 1995;18(1):7–15.7866980
153 Woloschuk DM, Raymond CB. Development and evaluation of a workplace-based preceptor training course for pharmacy practitioners. Canadian Pharmacists Journal. 2012;145(5):231–6.23509572
154 Wray LO, Ritchie MJ, Oslin DW, . Enhancing implementation of measurement-based mental health care in primary care: a mixed-methods randomized effectiveness evaluation of implementation facilitation. BMC Health Serv Res. 2018;18(1):753.30285718
155 Young D, Furler J, Vale M, . Patient Engagement and Coaching for Health: The PEACH study - A cluster randomised controlled trial using the telephone to coach people with type 2 diabetes to engage with their GPs to improve diabetes care: A study protocol. BMC Fam Pract. 2007;8.