# APPENDIX C IMPLEMENTATION STRATEGIES TABLE

For full study citations, please refer to the main report’s reference list.

Coaching Strategy | Dickinson, 2019^38^ | Carroll, 2018^39^ | Harris, 2015^55^ | Liddy, 2015^52^ | Parchman, 2013^43^ | Mold, 2014^40^ | Meropol, 2014^41^ | Dickinson, 2014^42^ | Hogg, 2008^53^ | Chinman, 2017^44^ | van Bruggen, 2008^48^ | Goodwin, 2001^18^ | Lemelin, 2001^54^ | Rask, 2001^45^ | Lobo, 2002^51^ | Due, 2014^49^ | Engels, 2006^50^ | Margolis, 2004^46^ | Ornstein, 2004^47^
Develop a formal implementation plan | ✕ | ✕ | ✕ | ✕ | ✕ | ✕ | ✕ | ✕ | ✕ | ✕ | ✕ | ✕ | ✕ | | ✕ | ✕ | ✕ | ✕ | ✕
Audit and provide feedback | ✕ | ✕ | ✕ | ✕ | ✕ | ✕ | ✕ | ✕ | ✕ | ✕ | ✕ | ✕ | ✕ | ✕ | ✕ | | ✕ | | ✕
Develop/distribut e educational materials | | | ✕ | ✕ | ✕ | ✕ | ✕ | | ✕ | | ✕ | ✕ | ✕ | ✕ | ✕ | | | ✕ | ✕
Conduct educational outreach visits | | ✕ | ✕ | | ✕ | ✕ | ✕ | | | ✕ | ✕ | | | ✕ | ✕ | ✕ | | ✕ | ✕
Provide ongoing consultation/ purposely reexamine the implementation | ✕ | ✕ | | | ✕ | | | ✕ | ✕ | ✕ | | | ✕ | | | ✕ | ✕ | ✕
Revise professional roles | ✕ | | ✕ | ✕ | ✕ | | | ✕ | ✕ | | | ✕ | | | | | | ✕
Provide local technical assistance/ | ✕ | ✕ | | ✕ | ✕ | | | | | ✕ | | ✕ | ✕
centralize technical assistance
Conduct local need assessment | ✕ | | | | ✕ | | ✕ | ✕ | | | | ✕ | | | | ✕ | ✕
Conduct cyclical small tests of change/develop and implement tools for quality monitoring/ develop and organize quality monitoring systems | | ✕ | | ✕ | | ✕ | ✕ | ✕ | | | | | | | | | ✕ | ✕
Create a learning collaborative | | ✕ | | ✕ | | | | ✕ | | | | | ✕ | | | | | | ✕
Develop resource sharing agreements | ✕ | | ✕ | ✕ | ✕
Organize clinician implementation team meetings | | ✕ | | | ✕ | | | | | | | | | | ✕
Build a coalition/conduct local consensus discussions/ | | ✕
obtain and use patients/ consumers and family feedback