# APPENDIX B STUDY CHARACTERISTICS TABLES

For full study citations, please refer to the main report’s reference list.

## KEY QUESTION 1

## KEY QUESTION 2