# APPENDIX A SEARCH STRATEGIES

## KEY QUESTION 1

### Database: MEDLINE (via Ovid)

Search date: 10/8/2019

1 | ((coach or coaches or coaching or mentor or mentors or mentorship or leader or leaders or leadership) and transformational).ti,ab. | 953
2 | ((coach or coaches or coaching) adj3 (practice or unit or “health system” or “health systems” OR clinical OR QI OR “quality improvement” OR interprofessional OR “practice enhancement“)).ti,ab. | 402
3 | ((advisor or advisors) adj4 (practice or “health system” or “health systems” or unit or “practice enhancement”)).ti,ab. | 37
4 | ((assistant or assistants) adj4 “practice enhancement”).ti,ab. | 6
5 | (external adj4 internal adj4 (facilitator or facilitators or facilitation)).ti,ab. | 46
6 | (“practice champion” or “practice champions” or “practice moderator” or “practice moderators” or “coach strategy” or “coaching strategy” or “coach strategies” or “coaching strategies” or “practice facilitator” or “practice facilitators” or “practice facilitation” or “project facilitator” or “project facilitators” or “project facilitation” or “change agent” or “change agents” or “facilitation intervention” OR “implementation facilitator” OR “implementation facilitators” OR “implementation facilitation” OR “nurse facilitator” OR “nurse facilitators” OR “nurse facilitation“).ab,ti. | 1359
7 | 1 or 2 or 3 or 4 or 5 or 6 | 2769
8 | exp Evaluation Studies as Topic/ | 1016800
9 | exp Cohort Studies/ | 1906026
10 | exp Longitudinal Studies/ | 127276
11 | randomized controlled trial.pt. | 491034
12 | controlled clinical trial.pt. | 93308
13 | comparative study.pt. | 1841804
14 | clinical trial.pt. | 518304
15 | evaluation studies.pt. | 246280
16 | (randomized or randomised or randomization or randomisation or placebo or randomly or trial or groups or “clinical trial” or “clinical trials” or “evaluation study” or “evaluation studies” or “intervention study” or “intervention studies” or cohort or longitudinal or longitudinally or prospective or prospectively or “follow up” or “comparative study” or “comparative studies” or nonrandom or “non-random” or nonrandomized or “non-randomized” or nonrandomised or “non–randomised“).ti,ab. | 4415642
17 | (quasi-experiment* or quasiexperiment* or quasirandom* or quasi-random* or quasi-control* or quasicontrol*).ti,ab. | 17600
18 | (“pre-post” or posttest or “post-test” or pretest or “pre-test” or “repeated measure” or “repeated measures“).ti,ab. | 68961
19 | (before and after).ti,ab. | 712412
20 | (before and during).ti,ab. | 373111
21 | (“time series” and interrupt*).ti,ab. | 2792
22 | (“time points” and (multiple or one or two or three or four or five or six or seven or eight or nine or ten or month or monthly or day or daily or week or weekly or hour or hourly)).ti,ab. | 60555
23 | 8 or 9 or 10 or 11 or 12 or 13 or 14 or 15 or 16 or 17 or 18 or 19 or 20 or 21 or 22 | 7628476
24 | 7 and 23 | 944

### Database: EMBASE (via Elsevier)

Search date: 10/8/2019

1 | ((coach:ab,ti or coaches:ab,ti or coaching:ab,ti or mentor:ab,ti or mentors:ab,ti or mentorship:ab,ti or leader:ab,ti or leaders:ab,ti or leadership:ab,ti) and transformational:ab,ti) | 1002
2 | ((coach or coaches or coaching) NEAR/4 (practice or unit or ‘health system’ or ‘health systems’ OR clinical OR QI OR ‘quality improvement’ OR interprofessional OR ‘practice enhancement’)):ab,ti | 698
3 | ((advisor or advisors) NEAR/4 (practice or ‘health system’ or ‘health systems’ or unit or ‘practice enhancement’)):ab,ti | 53
4 | ((assistant or assistants) NEAR/4 ‘practice enhancement’):ab,ti | 6
5 | (external NEAR/4 internal NEAR/4 (facilitator or facilitators or facilitation)):ab,ti | 53
6 | (’practice champion’ or ‘practice champions’ or ‘practice moderator’ or ‘practice moderators’ or ‘coach strategy’ or ‘coaching strategy’ or ‘coach strategies’ or ‘coaching strategies’ or ‘practice facilitator’ or ‘practice facilitators’ or ‘practice facilitation’ or ‘project facilitator’ or ‘project facilitators’ or ‘project facilitation’ or ‘change agent’ or ‘change agents’ or ‘facilitation intervention’ OR ‘implementation facilitator’ OR ‘implementation facilitators’ OR ‘implementation facilitation’ OR ‘nurse facilitator’ OR ‘nurse facilitators’ OR ‘nurse facilitation’):ab,ti | 1592
7 | 1 or 2 or 3 or 4 or 5 or 6 | 3358
8 | ’randomized controlled trial’/exp OR ‘crossover procedure’/exp OR ‘double blind procedure’/exp OR ‘single blind procedure’/exp OR randomization^,ab OR randomisation:ti,ab OR randomized:ti,ab OR randomised:ti,ab OR randomly:ti,ab OR crossover:ti,ab OR ‘cross over’:ti,ab OR placebo:ti,ab OR ‘double blind’:ti,ab OR ‘double blinded’:ti,ab OR ‘single blind’:ti,ab OR ‘single blinded’:ti,ab OR ‘clinical study’/exp OR ‘clinical trial’:ti,ab OR ‘clinical trials’:ti,ab OR ‘controlled study’/exp OR ‘evaluation study’/exp OR ‘evaluation study’:ti,ab OR ‘evaluation studies’:ti,ab OR ‘intervention study’/exp OR ‘intervention study’:ti,ab OR ‘intervention studies’:ti,ab OR ‘case control study’/exp OR ‘case control’:ti,ab OR ‘cohort analysis’/exp OR cohort:ti,ab OR cohorts:ti,ab OR longitudinal:ti,ab OR longitudinally:ti,ab OR prospective:ti,ab OR prospectively:ti,ab OR retrospective:ti,ab OR ‘follow up’/exp OR ‘follow up’:ti,ab OR ‘comparative effectiveness’/exp OR ‘comparative study’/exp OR ‘comparative study’:ti,ab OR ‘comparative studies’:ti,ab | 15801633
9 | ’pre post’:ti,ab OR prepost:ti,ab OR ‘post test’:ti,ab OR posttest:ti,ab OR pretest:ti,ab OR ‘pre test’:ti,ab OR ‘quasi experiment’:ti,ab OR quasiexperiment:ti,ab OR ‘quasi experimental’:ti,ab OR quasiexperimental:ti,ab OR quasirandom:ti,ab OR ‘quasi random’:ti,ab OR ‘quasi control’:ti,ab OR quasicontrol:ti,ab OR ‘repeated measure’:ti,ab OR ‘repeated measures’:ti,ab | 114686
10 | (’time series’:ti,ab AND interrupts,ab) OR (before:ti,ab AND after:ti,ab) OR (before:ti,ab AND during:ti,ab) | 1250928
11 | ’time points’:ti,ab AND (multiple:ti,ab OR one:ti,ab OR two:ti,ab OR three:ti,ab OR four:ti,ab OR five:ti,ab OR six:ti,ab OR seven:ti,ab OR eight:ti,ab OR nine:ti,ab OR ten:ti,ab OR month:ti,ab OR monthly:ti,ab OR day:ti,ab OR days:ti,ab OR daily:ti,ab OR week:ti,ab OR weekly:ti,ab OR hour:ti,ab OR hourly:ti,ab) | 102813
12 | 8 OR 9 OR 10 OR 11 | 16230359
13 | 7 AND 12 | 1176

### Database: CINAHL Complete (via EBSCO)

Search date: 10/8/2019

1 | TI (coach or coaches or coaching or mentor or mentors or mentorship or leader or leaders or leadership) OR AB (coach or coaches or coaching or mentor or mentors or mentorship or leader or leaders or leadership) | 68060
2 | TI (transformational) OR AB (transformational) | 1888
3 | 1 AND 2 | 1131
4 | TI (“practice coach” OR “practice coaches” OR “practice coaching” OR “unit coach” OR “unit coaches” OR “unit coaching” OR “health system coach” OR “health system coaches” OR “health system coaching” OR “clinical coach” OR “clinical coaches” OR “clinical coaching” OR “QI coach” OR “QI coaches” OR “QI coaching” OR “quality improvement coach” OR quality improvement coaches” OR “quality improvement coaching” OR “interprofessional coach” OR “interprofessional coaches” OR “interprofessional coaching” OR “practice enhancement coach” OR “practice enhancement coaching” OR “practice enhancement coaches“) OR AB TI (“practice coach” OR “practice coaches” OR “practice coaching” OR “unit coach” OR “unit coaches” OR “unit coaching” OR “health system coach” OR “health system coaches” OR “health system coaching” OR “clinical coach” OR “clinical coaches” OR “clinical coaching” OR “QI coach” OR “QI coaches” OR “QI coaching” OR “quality improvement coach” OR quality improvement coaches” OR “quality improvement coaching” OR “interprofessional coach” OR “interprofessional coaches” OR “interprofessional coaching” OR “practice enhancement coach” OR “practice enhancement coaching” OR “practice enhancement coaches“) | 33
5 | TI (advisor OR advisors) OR AB (advisor OR advisors) | 6145
6 | TI (practice or “health system” or “health systems” or unit or “practice enhancement“) OR AB (practice or “health system” or “health systems” or unit or “practice enhancement“) | 514841
7 | 5 AND 6 | 496
8 | TI (assistant or assistants) OR AB (assistant OR assistants) | 14849
9 | TI ("practice enhancement") OR AB ("practice enhancement") | 26
10 | 8 AND 9 | 4
11 | TI (external AND internal) OR AB (external AND internal) | 10758
12 | TI (facilitator or facilitators or facilitation) OR AB (facilitator or facilitators or facilitation) | 15928
13 | 11 AND 12 | 154
14 | TI (“practice champion” or “practice champions” or “practice moderator” or “practice moderators” or “coach strategy” or “coaching strategy” or “coach strategies” or “coaching strategies” or “practice facilitator” or “practice facilitators” or “practice facilitation” or “project facilitator” or “project facilitators” or “project facilitation” or “change agent” or “change agents” or “facilitation intervention” OR “implementation facilitator” OR “implementation facilitators” OR “implementation facilitation” OR “nurse facilitator” OR “nurse facilitators” OR “nurse facilitation“) OR AB (“practice champion” or “practice champions” or “practice moderator” or “practice moderators” or “coach strategy” or “coaching strategy” or “coach strategies” or “coaching strategies” or “practice facilitator” or “practice facilitators” or “practice facilitation” or “project facilitator” or “project facilitators” or “project facilitation” or “change agent” or “change agents” or “facilitation intervention” OR “implementation facilitator” OR “implementation facilitators” OR “implementation facilitation” OR “nurse facilitator” OR “nurse facilitators” OR “nurse facilitation“) | 1103
15 | 3 OR 4 OR 7 OR 10 OR 13 OR 14 | 2896
16 | (MH “Randomized Controlled Trials+“) OR TI (“randomized controlled trial” OR “controlled clinical trial” OR “randomized” OR “randomization” OR “randomised” OR “randomisation” OR “randomly” OR “trial” OR “groups” OR “comparative study” OR “nonrandom” OR “non-random” OR “nonrandomized” OR “non-randomized” OR “nonrandomised” OR “non-randomised” OR quasi-experiment* OR quasiexperiment* OR quasirandom* OR quasi-random* OR quasi-control* OR quasicontrol* OR (controlled AND (trial OR study)) OR “pre-post” OR “posttest” OR “post-test” OR “pretest” OR “pre-test” OR “repeated measure” OR “repeated measures” OR (“time series” AND “interrupt“) OR (“time points” AND (multiple OR one OR two OR three OR four OR five OR six OR seven OR eight OR nine OR ten OR month OR monthly OR day OR daily OR week OR weekly OR hour OR hourly)) OR (before AND after) OR (before AND during)) OR AB (“randomized controlled trial” OR “controlled clinical trial” OR “randomized” OR “randomization” OR “randomised” OR “randomisation” OR “randomly” OR “trial” OR “groups” OR “comparative study” OR “nonrandom” OR “non-random” OR “nonrandomized” OR “non-randomized” OR “nonrandomised” OR “non-randomised” OR quasi-experiment* OR quasiexperiment* OR quasirandom* OR quasi-random* OR quasi-control* OR quasicontrol* OR (controlled AND (trial OR study)) OR “pre-post” OR “posttest” OR “post-test” OR “pretest” OR “pre-test” “repeated measure” OR “repeated measures” OR (“time series” AND “interrupt“) OR (“time points” AND (multiple OR one OR two OR three OR four OR five OR six OR seven OR eight OR nine OR ten OR month OR monthly OR day OR daily OR week OR weekly OR hour OR hourly)) OR (before AND after) OR (before AND during)) | 775384
17 | 15 AND 16 | 489

## KEY QUESTION 2

### Database: MEDLINE (via Ovid)

Search date: 10/8/2019

1 | ((coach or coaches or coaching or mentor or mentors or mentorship or leader or leaders or leadership) and transformational).ti,ab. | 953
2 | ((coach or coaches or coaching) adj3 (practice or unit or “health system” or “health systems” OR clinical OR QI OR “quality improvement” OR interprofessional OR “practice enhancement“)).ti,ab. | 402
3 | ((advisor or advisors) adj4 (practice or “health system” or “health systems” or unit or “practice enhancement“)).ti,ab. | 37
4 | ((assistant or assistants) adj4 “practice enhancement”).ti,ab. | 6
5 | (external adj4 internal adj4 (facilitator or facilitators or facilitation)).ti,ab. | 46
6 | (“practice champion” or “practice champions” or “practice moderator” or “practice moderators” or “coach strategy” or “coaching strategy” or “coach strategies” or “coaching strategies” or “practice facilitator” or “practice facilitators” or “practice facilitation” or “project facilitator” or “project facilitators” or “project facilitation” or “change agent” or “change agents” or “facilitation intervention” OR “implementation facilitator” OR “implementation facilitators” OR “implementation facilitation” OR “nurse facilitator” OR “nurse facilitators” OR “nurse facilitation“).ab,ti. | 1359
7 | 1 or 2 or 3 or 4 or 5 or 6 | 2769
8 | exp qualitative research/ | 49182
9 | exp Focus Groups/ | 27720
10 | exp Interviews as Topic/ | 58980
11 | “Surveys and Questionnaires”/ | 438043
12 | exp Health Care Surveys/ | 35787
13 | (qualitative or qualitatively or interview or interviewed or interviews or interviewing or interviewer or interviewers or survey or surveys or surveyed or surveying or questionnaire or questionnaires or “focus group” or “focus groups” or “mixed method” or “mixed methods” or theme or themes or thematic or “group discussion” or “group discussions“).ab.ti. | 1429055
14 | 8 or 9 or 10 or 11 or 12 or 13 | 1575514
15 | 7 AND 14 | 1091
16 | 15 NOT (case reports.pt OR editorial.pt OR letter.pt OR comment.pt) | 1084

### Database: EMBASE (via Elsevier)

Search date: 10/8/2019

1 | ((coach:ab,ti or coaches:ab,ti or coaching:ab,ti or mentor:ab,ti or mentors:ab,ti or mentorship:ab,ti or leader:ab,ti or leaders:ab,ti or leadership:ab,ti) and transformational:ab,ti) | 1002
2 | ((coach or coaches or coaching) NEAR/4 (practice or unit or ‘health system’ or ‘health systems’ OR clinical OR QI OR ‘quality improvement’ OR interprofessional OR ‘practice enhancement’)):ab,ti | 698
3 | ((advisor or advisors) NEAR/4 (practice or ‘health system’ or ‘health systems’ or unit or ‘practice enhancement’)):ab,ti | 53
4 | ((assistant or assistants) NEAR/4 ‘practice enhancement’):ab,ti | 6
5 | (external NEAR/4 internal NEAR/4 (facilitator or facilitators or facilitation)):ab,ti | 53
6 | (’practice champion’ or ‘practice champions’ or ‘practice moderator’ or ‘practice moderators’ or ‘coach strategy’ or ‘coaching strategy’ or ‘coach strategies’ or ‘coaching strategies’ or ‘practice facilitator’ or ‘practice facilitators’ or ‘practice facilitation’ or ‘project facilitator’ or ‘project facilitators’ or ‘project facilitation’ or ‘change agent’ or ‘change agents’ or ‘facilitation intervention’ OR ‘implementation facilitator’ OR ‘implementation facilitators’ OR ‘implementation facilitation’ OR ‘nurse facilitator’ OR ‘nurse facilitators’ OR ‘nurse facilitation’):ab,ti | 1592
7 | 1 or 2 or 3 or 4 or 5 or 6 | 3358
8 | ’qualitative research’/exp OR ‘interview’/exp OR ‘surveys’/exp OR ‘questionnaire’/exp OR ‘mixed methods’/exp | 926104
9 | (qualitative or qualitatively or interview or interviewed or interviews or interviewing or interviewer or interviewers or survey or surveys or surveyed or surveying or questionnaire or questionnaires or ‘focus group’ or ‘focus groups’ or ‘mixed method’ or ‘mixed methods’ or theme or themes or thematic or ‘group discussion’ or ‘group discussions’):ab,ti | 1930573
10 | 8 OR 9 | 2087733
11 | 7 AND 10 | 1369
12 | 11 NOT (’case report’/exp OR ‘case study’/exp OR ‘editorial’/exp OR ‘letter’/exp OR ‘note’/exp OR [conference abstract]/lim) | 1062

### Database: CINAHL Complete (via EBSCO)

Search date: 10/8/2019

1 | TI (coach or coaches or coaching or mentor or mentors or mentorship or leader or leaders or leadership) OR AB (coach or coaches or coaching or mentor or mentors or mentorship or leader or leaders or leadership) | 68060
2 | TI (transformational) OR AB (transformational) | 1888
3 | 1 AND 2 | 1131
4 | TI (“practice coach” OR “practice coaches” OR “practice coaching” OR “unit coach” OR “unit coaches” OR “unit coaching” OR “health system coach” OR “health system coaches” OR “health system coaching” OR “clinical coach” OR “clinical coaches” OR “clinical coaching” OR “QI coach” OR “QI coaches” OR “QI coaching” OR “quality improvement coach” OR quality improvement coaches” OR “quality improvement coaching” OR “interprofessional coach” OR “interprofessional coaches” OR “interprofessional coaching” OR “practice enhancement coach” OR “practice enhancement coaching” OR “practice enhancement coaches“) OR AB TI (“practice coach” OR “practice coaches” OR “practice coaching” OR “unit coach” OR “unit coaches” OR “unit coaching” OR “health system coach” OR “health system coaches” OR “health system coaching” OR “clinical coach” OR “clinical coaches” OR “clinical coaching” OR “QI coach” OR “QI coaches” OR “QI coaching” OR “quality improvement coach” OR quality improvement coaches” OR “quality improvement coaching” OR “interprofessional coach” OR “interprofessional coaches” OR “interprofessional coaching” OR “practice enhancement coach” OR “practice enhancement coaching” OR “practice enhancement coaches“) | 33
5 | TI (advisor OR advisors) OR AB (advisor OR advisors) | 6145
6 | TI (practice or “health system” or “health systems” or unit or “practice enhancement“) OR AB (practice or “health system” or “health systems” or unit or “practice enhancement“) | 514841
7 | 5 AND 6 | 496
8 | TI (assistant or assistants) OR AB (assistant OR assistants) | 14849
9 | TI ("practice enhancement") OR AB ("practice enhancement") | 26
10 | 8 AND 9 | 4
11 | TI (external AND internal) OR AB (external AND internal) | 10758
12 | TI (facilitator or facilitators or facilitation) OR AB (facilitator or facilitators or facilitation) | 15928
13 | 11 AND 12 | 154
14 | TI (“practice champion” or “practice champions” or “practice moderator” or “practice moderators” or “coach strategy” or “coaching strategy” or “coach strategies” or “coaching strategies” or “practice facilitator” or “practice facilitators” or “practice facilitation” or “project facilitator” or “project facilitators” or “project facilitation” or “change agent” or “change agents” or “facilitation intervention” OR “implementation facilitator” OR “implementation facilitators” OR “implementation facilitation” OR “nurse facilitator” OR “nurse facilitators” OR “nurse facilitation“) OR AB (“practice champion” or “practice champions” or “practice moderator” or “practice moderators” or “coach strategy” or “coaching strategy” or “coach strategies” or “coaching strategies” or “practice facilitator” or “practice facilitators” or “practice facilitation” or “project facilitator” or “project facilitators” or “project facilitation” or “change agent” or “change agents” or “facilitation intervention” OR “implementation facilitator” OR “implementation facilitators” OR “implementation facilitation” OR “nurse facilitator” OR “nurse facilitators” OR “nurse facilitation“) | 1103
15 | 3 OR 4 OR 7 OR 10 OR 13 OR 14 | 2896
16 | (MH “Qualitative Studies+“) OR (MH “Focus Groups“) OR (MH “lnterviews+“) OR (MH “Surveys“) OR (MH “Narratives+“) OR TI (qualitative OR qualitatively OR interview OR interviewed OR interviews OR interviewing OR interviewer OR interviewers OR survey OR surveys OR surveyed OR surveying OR questionnaire OR questionnaires OR “focus group” OR “focus groups” OR “mixed method” OR “mixed methods” OR theme OR themes OR thematic “group discussion” OR “group discussions“) OR AB (qualitative OR qualitatively OR interview OR interviewed OR interviews OR interviewing OR interviewer OR interviewers OR survey OR surveys OR surveyed OR surveying OR questionnaire OR questionnaires OR “focus group” OR “focus groups” OR “mixed method” OR “mixed methods” OR theme OR themes OR thematic OR “group discussion” OR “group discussions“) | 725243
17 | 15 AND 16 | 1208