# REFERENCES

1 Bodenheimer T, Laing BY. The teamlet model of primary care. Ann Fam Med. 2007;5(5):457–461.17893389
2 Higgins JP, Altman DG, Gotzsche PC, . The Cochrane Collaboration’s tool for assessing risk of bias in randomised trials. Bmj. 2011;343:d5928.22008217
3 Sterne JA, Hernan MA, Reeves BC, . ROBINS-I: a tool for assessing risk of bias in non-randomised studies of interventions. Bmj. 2016;355:i4919.27733354
4 The GRADE Working Group. https://www.gradeworkinggroup.org/. Published 2020. Accessed.
5 Bower P, Campbell S, Bojke C, Sibbald B. Team structure, team climate and the quality of care in primary care: an observational study. Qual Saf Health Care. 2003;12(4):273–279.12897360
6 Bruhl EJ, MacLaughlin KL, Allen SV, . Association of Primary Care Team Composition and Clinician Burnout in a Primary Care Practice Network. Mayo Clin Proc Innov Qual Outcomes. 2020;4(2):135–142.32280923
7 Meyers D, LeRoy L, Bailit M, Schaefer J, Wagner E, Zhan C. Workforce Configurations to Provide High-Quality, Comprehensive Primary Care: a Mixed-Method Exploration of Staffing for Four Types of Primary Care Practices. J Gen Intern Med. 2018;33(10):1774–1779.29971635
8 Ovhed I, Johansson E, Odeberg H, Rastam L. A comparison of two different team models for treatment of diabetes mellitus in primary care. Scand J Caring Sci. 2000;14(4):253–258.12035216
9 Basu S, Phillips RS, Bitton A, Song Z, Landon BE. Finance and Time Use Implications of Team Documentation for Primary Care: A Microsimulation. Ann Fam Med. 2018;16(4):308–313.29987078
10 D’Afflitti J, Lee K, Jacobs M, . Improving Provider Experience and Increasing Patient Access Through Nurse Practitioner-Physician Primary Care Teams. J Ambulatory Care Manage. 2018;41(4):308–313.30148771
11 Dai M, Ingham RC, Peterson LE. Scope of Practice and Patient Panel Size of Family Physicians Who Work With Nurse Practitioners or Physician Assistants. Fam Med. 2019;51(4):311–318.30973618
12 Litaker D, Mion L, Planavsky L, Kippes C, Mehta N, Frolkis J. Physician - nurse practitioner teams in chronic disease management: the impact on costs, clinical effectiveness, and patients’ perception of care. J Interprof Care. 2003;17(3):223–237.12850874
13 Shaw RJ, McDuffie JR, Hendrix CC, Edie A, Lindsey-Davis L, Williams JW, Jr. Effects of Nurse-Managed Protocols in the Outpatient Management of Adults with Chronic Conditions. Department of Veterans Affairs. 2013;08:08.
14 Wranik WD, Price S, Haydt SM, . Implications of interprofessional primary care team characteristics for health services and patient health outcomes: A systematic review with narrative synthesis. Health Policy. 2019;123(6):550–563.30955711
15 Dorr DA, Wilcox A, Burns L, Brunker CP, Narus SP, Clayton PD. Implementing a multidisease chronic care model in primary care using people and technology. Dis Manage. 2006;9(1):1–15.
16 Stoeckle JJ, Cunningham A, Al-Hawarri D, Silverio A, Valko G. The Effect of Primary Care Team Realignment on Point-of-Care Screening. Popul Health Manag. 2019;22(2):108–112.30016202
17 Brown-Johnson CG, Chan GK, Winget M, . Primary Care 2.0: Design of a Transformational Team-Based Practice Model to Meet the Quadruple Aim. Am J Med Qual. 2019;34(4):339–347.30409021
18 Crawford ER, Reeves CJ, Stewart GL, Astrove SL. To link or not to link? Multiple team membership and unit performance. J Appl Psychol. 2019;104(3):341–356.30640489
19 Wagner EH, Flinter M, Hsu C, . Effective team-based primary care: observations from innovative practices. BMC Fam Pract. 2017;18(1):13.28148227