# ACKNOWLEDGMENTS

This topic was developed in response to a nomination by Idamay Curtis, BA, Karin Nelson, MD, MSHS, and Greg Stewart, PhD for the purpose of identifying the structure and function of primary care team members to maximize patient and provider outcomes. The scope was further developed with input from the topic nominators (ie, Operational Partners), the ESP Coordinating Center, the review team, and the technical expert panel (TEP).

In designing the study questions and methodology at the outset of this report, the ESP consulted several technical and content experts. Broad expertise and perspectives were sought. Divergent and conflicting opinions are common and perceived as healthy scientific discourse that results in a thoughtful, relevant systematic review. Therefore, in the end, study questions, design, methodologic approaches, and/or conclusions do not necessarily represent the views of individual technical and content experts.

The authors gratefully acknowledge the following individuals for their contributions to this project:

## Operational Partners

Operational partners are system-level stakeholders who have requested the report to inform decision-making. They recommend Technical Expert Panel (TEP) participants; assure VA relevance; help develop and approve final project scope and timeframe for completion; provide feedback on draft report; and provide consultation on strategies for dissemination of the report to field and relevant groups.

- Idamay Curtis, BA
  Co-Director of the Office of Primary Care Analytics Team
  VA Puget Sound Health Care System
- Karin Nelson, MD, MSHS
  Director, Primary Care Analytic Team, VHA Office of Primary Care
  Professor of Medicine, University of Washington
- Greg Stewart, PhD
  Professor of Management and Entrepreneurship
  University of Iowa, Tippie College of Business

## Technical Expert Panel (TEP)

To ensure robust, scientifically relevant work, the TEP guides topic refinement; provides input on key questions and eligibility criteria, advising on substantive issues or possibly overlooked areas of research; assures VA relevance; and provides feedback on work in progress. TEP members are listed below:

- Lisa Rubenstein, MD, MS
  Professor of Medicine and Public Health, VA Greater Los Angeles and UCLA
  Senior Natural Scientist, RAND
- Ann-Marie Rosland, MD, MS
  Associate Professor, Internal Medicine, University of Pittsburgh Department of Medicine
  Research Scientist, VA Center for Health Equity and Promotion, VA Pittsburgh Healthcare System
- Stephan Fihn, MD, MPH
  Physician and Professor, Division of General Internal Medicine, University of Washington
- Sylvia Hysong, PhD
  Associate Professor, Department of Medicine, Baylor College of Medicine
  Lead Research Health Scientist, VA Medical Center, Houston, Texas

## Peer Reviewers

The Coordinating Center sought input from external peer reviewers to review the draft report and provide feedback on the objectives, scope, methods used, perception of bias, and omitted evidence. Peer reviewers must disclose any relevant financial or non-financial conflicts of interest. Because of their unique clinical or content expertise, individuals with potential conflicts may be retained. The Coordinating Center and the ESP Center work to balance, manage, or mitigate any potential nonfinancial conflicts of interest identified.