# SUMMARY OF FINDINGS/CERTAINTY OF EVIDENCE

The evidence on what matters in terms of composition of the teamlet is very sparse, consisting of a few hypothesis-testing studies that address only partial aspects of the question, and modeling studies. The most robust evidence is that adding a dedicated chronic care manager can improve some outcomes for some patients – although in the prior ESP review of nurse-managed protocols study the nurse charged with doing this required prescribing authority, which is not something VA teamlet RNs currently have. We rated this as moderate-certainty evidence based on 1 RCT that found better outcomes for patients with diabetes but no difference in hypertension outcomes and 1 longitudinal study with a control group that found better outcomes for diabetes and depression care, and augmented this with the results of the 1 high-quality ESP review on nurse-managed protocols (which assessed effects on care for a number of conditions, such as diabetes, lipid control, and hypertension). Our rating of moderate certainty of evidence is supported as follows: there are 3 studies relevant to this question, 1 RCT, 1 observational study with a concurrent control group, and 1 ESP systematic review on a related topic. The RCT was judged as being at unknown risk of bias on 2 important domains, and thus for the domain of “study limitations” this body of evidence was rated as having a serious limitation. Both of the 2 original research studies reached similar (favorable) conclusions regarding the addition of a dedicated chronic care manager, and thus we judged the domain of inconsistency as having no serious inconsistency. We did not judge either study as having a serious limitation in the directness of the evidence, as they measured well-accepted outcomes for chronic conditions and were (by definition) interventions that added a chronic care manager to an existing team structure. We also did not judge these studies as having a serious limitation with respect to imprecision, not because we believed that the added benefit of the chronic care manager was precisely estimated and similar in both studies, but rather that the reported benefit in the studies exceeded commonly used thresholds for other interventions being deemed worth doing (such as the approximately 0.5 point decrease in HgbA1c, an effect size commonly seen with addition of certain drugs). Thus, both studies exceeded the “decision threshold”, and were sufficiently precise to conclude that the intervention was “worth doing”. The column headed “Other Factors” is where we considered the existing ESP review on nurse-managed protocols, which concluded that there was moderate-certainty evidence that their use resulted in beneficial outcomes for a host of chronic conditions. The synthesis of all these factors led us to conclude that the certainty of evidence is moderate for adding a dedicated chronic care manager to an existing primary care team. Similar reasoning led us to conclude that there is low-certainty evidence, based on a single study each, that adding NPs as co-managers to a physician teamlet increases access (as measured by the 3^rd^ next available appointment), that re-training medical assistants to perform screening increases screening rates, and that differing patient populations will require differing mixes of team skill FTE in order to deliver high-quality care. See Table 4 for details. We did not include as “findings” or rate for certainty of evidence conclusions based on results of single studies that were cross-sectional or pre-post in design. Thus only 6 studies contribute evidence to “findings”.

Not included as evidence per se, but relevant to these findings, are the results of in-depth case studies of 30 primary care practices viewed as innovators in team-based care, as part of the LEAP (Learning from Effective Ambulatory Practices) program from the Robert Wood Johnson Foundation.^19^ Key findings of these case studies are that practices have expanded the role of existing staff (as seen in the medical assistants-trained-to-screen study and the Swedish study expanding the role of RNs), and added new personnel (such as the chronic care manager studies) to provide capacity and skills needed to provide care consistent with the patient-centered medical home model. For the care of complex patients most teams have behavioral health specialists, RN care managers, and pharmacists (also noted in the modeling study described above).

Table 4 Certainty of Evidence

Intervention or Outcome | Number of studies | Study limitations | Consistency | Directness | Precision | Other factors | Overall Certainty of Evidence
Adding NP or other dedicated chronic care manager improving outcomes of some chronic conditions (most notably diabetes, but not hypertension) | 3 | Serious | No serious inconsistency | No serious indirectness | No serious imprecision | Moderate certainty evidence that nurse-managed protocols result in improvements in multiple outcomes for patients with chronic conditions | Moderate
Adding NPs as co-management providers increases access | 1 | Very serious | N/A | No serious indirectness | No serious imprecision | None | Low
Retraining medical assistants to screen patients for certain conditions can increase the proportion of patients screened | 1 | No serious limitation | N/A | No serious indirectness | No serious imprecision | None | Low
3.6 to 4.0 FTE of supporting team members are needed for each 1.0 FTE of physician to deliver high-quality comprehensive care; different mixes of skillsets and staffing needed for differing patient populations | 1 | Serious limitations | N/A | No serious indirectness | No serious imprecision | Modeling study (Limitation: modeling study) | Low

## LIMITATIONS

### Publication Bias

The primary limitation to this review is the paucity of hypothesis-testing studies on the subject. Only 5 studies had a longitudinal component to their data collection. Cross-sectional studies such as those identified in this review have only a very limited ability to support causal conclusions. A second limitation is the possibility of publication bias. Certainly there must have been more implementations and potentially evaluations of differing team compositions than the published studies we identified. How this publication bias might influence our conclusions is unknown.

### Study Quality

As noted, study quality is a major concern for this topic. While some of the studies used a longitudinal design and might be able to support causal relationships, most did not.

### Heterogeneity

Heterogeneity is a major concern for this topic. Studies’ interventions most often included multiple components, and these were all idiosyncratic—no study tested the same intervention, in all its components, as any other study. We attempted to group study interventions into categories of interventions that shared some similarities, but nevertheless within each category there is still substantial heterogeneity in interventions.

### Applicability of Findings to the VA Population

We found only 1 study in a VA population, and it was about single versus multiple team membership roles, and not about specific team members. We can only speculate as to the applicability of the remaining findings to VA populations. At least 1 of the interventions – nurse-managed protocols that require prescribing authority – is not currently available within VA.

## RESEARCH GAPS/FUTURE RESEARCH

VA would seem to be ideally placed to provide experimental evidence about how teamlet and team structures can be optimized. Almost every VA of sufficient size organizes their teamlets into larger units (like Red, Blue, or Yellow teams). This would then allow for controlled comparisons of differing team and teamlet structures, with other contextual features being internally controlled (like senior leadership, incentives, and the EHR). For example, any of the recommended team staffing levels in the model of Meyers for either their “high geriatric” or their “high social needs” models could be implemented in 1 larger team (Red, Green, Blue) while the others serve as control. Teamlet structure could be varied (for example, 1 RN for every 2 physician providers) or team structures could be varied (for example, adding the 1.0 substance abuse counselor). Data collection could come directly from the EHR. Detailed information would need to be collected about patients’ chronic conditions and social needs as the model by Meyers consider these important variables when determining optimal team composition. An agreed-upon metric for evaluating performance – presumably based on the triple aim – would facilitate comparisons of results across studies.

## CONCLUSIONS

The evidence for an optimal teamlet or team structure is very sparse. Other than adding a dedicated chronic care manager, there is no evidence above low certainty that any team structure is optimal. Complex patients almost certainly benefit from additional skills (beyond the basic teamlet of provider, medical assistant, and nurse) in the team writ large (such as pharmacist, chronic care manager, etc).