# RESULTS

## LITERATURE FLOW

We identified 3,464 potentially relevant citations. Inspection of the titles excluded 3,249 as being irrelevant, leaving 215 titles that were selected for abstract screening. From these, a total of 129 abstracts were excluded. Excluded abstracts were categorized as not research (n=27), not about specific team member roles in TBPC (n=24), not about TBPC (n=22), qualitative study (n=17), no relevant outcomes (n=8), no abstract (n=6), descriptive study (n=1), and study protocol (n=1). This left 86 publications for full-text review, of which 72 publications were excluded for the following reasons: not about specific team member roles in TBPC (n=32), not about TBPC (n=10), adding pharmacists (n=8), no outcome of interest (n=7), qualitative study (n=4), not available (n=4), not research (n=2), background (n=1), descriptive (n=1), not primary care (n=1), non-systematic review (n=1), and study protocol (n=1). A full list of excluded studies from the full-text review is included in Appendix C. A total of 14 publications were identified at full-text review as meeting initial inclusion criteria. This included 5 studies that showed comparative study of different team structures,^5–8^ 8 studies that added a provider in context of team-based care,^9–16^ and 1 study that assessed outcomes when going from a structure that was not team-based to a structure that was.^17^ See Figure 1 for literature flow. Descriptions of included publications are available in Tables 2 and 3.

Figure 1 Literature Flow Chart

## DESCRIPTION OF THE EVIDENCE

We identified 1 randomized trial.^12^ Of the 5 studies comparing 2 different team structures, 1 was a longitudinal observational study,^8^ 3 were cross-sectional studies,^5,6,18^ and 1 was a modeling study.^8^ (See Table 1. Description of Evidence). Three studies were in US primary care,^6,7,18^ 1 study was from England general practices,^7^ and the remaining study was in Sweden.^8^ The team members studies included physicians and nurses. The outcomes assessed were clinical quality in 4 studies,^8,12,15,16^ physician burnout in 1 study,^6^ and a composite of “high-quality, comprehensive care”.^8^ Of the 7 studies about adding a team member, 2 were systematic reviews,^13,14^ 2 were longitudinal studies,^12,15^ 1 was a pre-post study,^10^ and the last 1 was a modeling study.^9^ The 5 non-systematic review studies were all based in the US. Three of the studies were about adding a nurse practitioner (or physician assistant),^10–12^ 2 were about adding nurses,^13,14^ 1 was about adding a medical scribe or medical assistant,^9^ and 1 was about adding a care manager.^15^ Outcomes assessed clinical quality, costs, access, and panel size (which we included as being related to access/costs). All included studies were at high risk of bias in at least 1 domain (see Appendix D).

Table 1 Description of the Evidence

Author, Year | Study Design | Location | Outcomes Assessed
Litaker, 2003^12^ | RCT | General internal medicine at Cleveland Clinic in Cleveland, Ohio, United States | Diabetes care, hypertension, preventative care, HRQOL
Dorr, 2006^15^ | Observational longitudinal with control | Intermountain Healthcare in Utah and Idaho, United States | Diabetes control, costs for depression care
Ovhed, 2000^8^ | Observational longitudinal with control | 2 primary health care centers in Blekinge county, South Sweden | Diabetes care practices
Stoeckle, 2019^16^ | Time series | Family medicine clinic in Philadelphia, Pennsylvania, United States | Screening for depression and falls
Brown-Johnson, 2019^17^ | Pre-post | Primary care clinic at an academic medical center | Clinic operations, wellness and proactive care, patient engagement and trust
D’Afflitti, 2018^10^ | Pre-post | General internal medicine practice at Boston Medical Center in Boston, Massachusetts | Access
Bower, 2003^5^ | Observational Cross-sectional | 60 primary care practices across England | Clinical quality for angina, asthma, diabetes
Bruhl, 2020^6^ | Observational Cross-sectional | 420 family medicine clinicians practicing in 59 Midwestern communities in the United States | Physician burnout
Crawford, 2019^18^ | Observational Cross-sectional | 849 VHA primary care units across the United States | “Unit performance” – Emergency Department visits
Dai, 2019^11^ | Cross-sectional survey | Family practices across the United States | Panel size
Basu, 2018^9^ | Model | 643 primary care practices across the United States | Costs
Meyers, 2018^7^ | Model | Multiple primary care practices across the United States | N/A
Shaw, 2013^13^ | Systematic review of 29 studies | Adult outpatient practices in Western Europe and the United States | Clinical quality resource use; nursing satisfaction
Wranik, 2019^14^ | Systematic review of 31 quantitative studies | Primary care sites in Australia, Canada, the United Kingdom, and New Zealand | Clinical process and outcomes

## KEY QUESTION WHAT ARE THE EFFECTS OF DIFFERENT PRIMARY CARE TEAM STRUCTURES ON CARE?

### Hypothesis-testing studies of 2 different primary care team structures

We identified 4 hypothesis-testing studies and 1 modeling study comparing different primary care team structures (Table 2).

Three studies assessed primary care in the US. The only study that was empirical and directly assessed an outcome of interest was by Bruhl and colleagues.^6^ In this cross-sectional study of 420 family medicine clinicians in 59 practices within 1 integrated health system, 217 (52%) responded to a survey containing a single item of the emotional exhaustion domain of physician burnout. Responding clinicians were working about 0.9 FTE and on teams consisting of on average 5 clinicians. Each clinician was responsible for a panel of about 1000 patients. In a multivariate linear mixed model regression analysis, an increasing proportion of physician FTE on the team (calculated by taking the physician FTE and dividing by the total care team clinician FTE) was associated with a modest reduction in burnout (that is, less burnout) – in the context of 85% of respondents indicating they were at high risk of burnout. As this study is cross-sectional in design the temporal relationship of this association cannot be discerned. The low response rate is another limitation of this study in drawing conclusions.

A second study assessed different team structures in US primary care, but via a model. The model estimated the staffing needed to provide “high-quality, comprehensive care” (not otherwise explicitly defined) for 4 exemplar patient populations: the index model, a model of a practice with a high proportion of geriatric patients, a model of a practice with a high proportion of patients with social needs, and a rural population model. Each of the first 3 models started with the goal of providing care to 10,000 patients, and then modeled how many providers and the skill mix that would be needed to provide high-quality care. The rural model assumed care for 5000 patients. The index model had 6.0 FTE MD providers and 2.0 FTE NP/PA providers, and required 3.6 FTE of supporting team members for each clinician, whereas this rose to 4.0 FTE for the high geriatric and high social needs models. The types of supporting FTE varied for each population. For example, the high geriatric model had more clinicians, more RNs, more social workers, and more dedicated care coordination FTE than the index model. The high social needs model had fewer physician providers and more NP/PA providers, more social workers, and a 1.0 FTE substance abuse counselor, in addition to community health workers. Strengths of this study are that it gives specific estimates for a broad array of skillsets needed for a primary care team, and it does so for different types of patient populations. Limitations are that it is a model, and what the model is optimizing – high-quality comprehensive care – is not defined in detail.

The remaining 2 studies assessed primary care team structures in England and Sweden. The Swedish study compared diabetes outcomes at 2 primary health care centers.^8^ In 1 center, local guidelines were implemented an independent role for nurses, who saw diabetic patients independently 3 times per year. The comparison clinic had a traditional Swedish arrangement where nurses were assistants to the physicians and did not work independently. In addition, no local guidelines were implemented. Over 1 year there were fewer physician visits and many more nursing visits at the clinic with independent nurses, and much more secondary prevention and testing of intermediate outcomes (HbA1c, lipids, retinal exams, etc) as well as more patient knowledge and self-efficacy. In the English study, 42 general practices were assessed for skill mix (ratio of doctors to nurses), team climate, and performance measures for several chronic diseases. In a multivariable model, skill mix was not a significant predictor variable for quality of chronic disease care.^5^

Lastly, Crawford and colleagues^18^ used data about team composition to assess the association of multiple team membership on patient Emergency Department use. Using national VA data on 849 primary care units (in hospitals and clinics) and a VA team membership report, they determined whether staff had single or multiple team membership, and how many teams a staff person participated in. They then used this as a predictor variable in a multivariable model that adjusted for patient care complexity, rural/urban location, average team size, and staff-to-provider ratio, assessing the association with Emergency Department visits by primary care unit patients. The analysis found a statistically significant association between an increasing number of team memberships and Emergency Department visits. This association was most pronounced for patients with the highest health needs (higher care complexity). The authors conclude that there is an association between multiple team memberships and worse unit performance (as measured by increasing Emergency Department use), but acknowledge that their cross-sectional study design cannot support conclusions about causation.

Table 2 Comparative Studies of Different Team Member Compositions

Author, Year | Study Design | Setting | Team Members Studied | Outcomes | Results
Bruhl, 2020^6^ | Observational Cross-sectional | 420 family medicine clinicians practicing in 59 Midwestern communities | Proportion of physician FTE on a team | Physician burnout | Increasing physician FTE on a team was associated with modest reductions in physician burnout in a setting of high risk for burnout
Meyers, 2018^7^ | Model | Multiple US primary care sites | MD/DDs; NPs/PAs; RN; LPN/LVN; MA | High-quality comprehensive care | Detailed specifications for skill sets and FTE to deliver high quality care under 4 different patient population scenarios
Bower, 2003^5^ | Observational Cross-sectional | 60 English general practices | Skill mix based on team composition:; Ratio of doctors: nurses; Ratio of doctors: non-medical clinical staff; Ratio of clinical: administrative staff | Clinical quality for angina, asthma, diabetes | Ratio of physicians to nurses not associated with changes in chronic care quality
Ovhed, 2000^8^ | Observational longitudinal with control; N=394 | 2 Swedish primary health care centers | Greater independent role for nurses in diabetes management | Diabetes care practices | Independence for nurses was associated with more secondary prevention and intermediate outcomes in patients with DM
Crawford, 2019^18^ | Observational Cross-sectional | 849 Veterans Health Administration primary care units | All team members, and the degree to which they were members of a single team or of multiple teams | Emergency Department visits | Units where staff are members of multiple teams had statistically significantly greater patient use of the Emergency Department, particularly for patients with greater health needs

### Studies of 2 different structures for the same team, measured at different time points

We did not identify any studies of this type.

### Adding a new team member to an established team

We identified 8 hypothesis-testing studies that assessed adding team members to an established primary care team: 5 empirical studies, 1 modeling study, and 2 systematic reviews (Table 3).

The only randomized trial we identified came from the Cleveland Clinic, and it compared traditional physician-only chronic disease management with “a more collaborative, team-based approach”, the key ingredient of which was adding a Nurse Practitioner trained in chronic care management. Additional intervention features included greater use of telephonic management and standardized forms to facilitate documentation of preventive care delivery.^12^ Patients with diabetes and hypertension were randomized (N=157) to 1 or the other and followed for 12 months. The mean age of subjects was about 61 years, more than half of patients were African American, and nearly 59% were female. Baseline A1c for patients with diabetes was 8.5, and 9% of patients met blood pressure target goals. A number of prevention measures and monitoring measures were performed more frequently in the intervention group (such as receipt of influenza vaccination by 78% vs 47%, p <0.001, foot exam in 100% vs 36%, etc) and as well as much more documentation of diabetic teaching. There were greater declines in A1c level in the intervention group (−0.63 vs −0.15, p=0.02) and increases in HDL (3.0 vs 0.4, p=0.02). There were no differences between groups in a number of other measures, including most HRQOL measures, an eye exam by an ophthalmologist, total cholesterol, and control of blood pressure. Personnel costs were greater in the intervention group. In a post-hoc analysis, after discontinuation of the trial and the return of patients to the “usual care” form of chronic disease management, A1c values climbed in the former intervention patients, and by 12 months there was no longer any difference between such patients and the control patients.

A study from Intermountain Healthcare also described their changes to deal with chronic disease care management.^15^ This included a reliance on the electronic health record to support information system needs and local evidence-based guidelines, but also the addition of a generalist care manager (ie, not restricted to a single disease). Each of the 7 primary care clinics had a dedicated care manager, who saw patients by referral from the primary care provider. The 3 most common reasons for referral to the care manager were diabetes, mental health, and social/organizational needs. Compared to patients that did not receive care management, those with care management (N=2,356) had a greater decrease in HbA1c (a reduction of 0.55% vs 0.18%, statistical testing not performed), increased primary care productivity (an increase of 8% vs 5.5%, statistical testing not performed), and decreased cost of care for patients with depression (8% decrease vs 19% increase, statistical testing not performed).

In a pre-post study from general internal medicine practice at Boston Medical Center, the “NP-Anchor” model of primary care was implemented.^10^ Prior to this, 8 clinic NPs functioned as independent primary care providers with their own patient panels. Due to high rates of job dissatisfaction, job stress, and burnout, after a successful pilot study the clinic staffing was re-configured such that 1 NP worked with 3-4 physicians (not all of whom were full time; the ratio of FTE was 1.0 NP to 1.5 physician) to co-manage patients. NPs no longer had their own patient panels. The target panel size for physicians was 1350; this did not change in the new configuration. NPs saw patients 6 half-days a week, and 2 additional half-days were devoted to chronic care management via telephone calls, test results follow-up, care coordination with specialists, and the like. Following implementation, the average time to the third next available appointment decreased nearly 20 days, from 26.2 days to 6.6 days (statistical testing not done). This was judged to be due to the NP adding capacity to the care team.

A cross-sectional survey of registrants for the American Board of Family Medicine Certification Examination (N=27,836; 100% response rate for the main survey, but only 42.5% or about 11,800 answered the panel size question), panel size was statistically significantly higher for practices that had an NP or a PA (or both), being 410 patients greater in practices with a PA, 259 greater in practices with an NP, and 245 greater in practices with both an NP and a PA.^11^ Overall, panel sizes were between 1900 and 2500 patients, depending on the size of the practice (solo practice to large practices, with smaller panels sizes the larger the practice). The low response rate to the primary outcome measure and the cross-sectional study design are both limitations of this study,

One study modeled the financial effect of adding a medical scribe or of having medical assistants complete the history, documentation, counseling, and order entry.^9^ The latter has been called the advanced team-based care (ATBC) strategy. The context was a fee-for-service primary care practice. The tradeoff was less physician time spent doing documentation, counseling, etcetera, which then opened up more time to see additional revenue-generating patients. In order to break even, use of the medical scribe would need to save 3.5 minutes per encounter, thus adding 317 visit slots per year, whereas the ATBC strategy would require saving 7.4 minutes per encounter, to enable the addition of 720 extra visit slots per year.

Although not technically a study of adding a team member, we include here a time-series study of re-defining the responsibilities of a medical assistant, to deal with screening.^16^ We judged that conceptually this addition of a skillset is closer to adding a team member than it is to any of our other categories. In this study, from the Thomas Jefferson family medicine clinic, medical assistants were trained and given responsibility for screening patients for depression and for falls. Over a span of 22 months, prior to implementing this change the screening rate for these conditions was essentially zero for depression, and 20% or less for falls. Immediately after implementation, the screening rate for depression increased to 30%, and continued to increase to 60% over the next 6 months. For falls, the screening rate jumped from about 23% to 45%, and then continued to increase over the next 6 months to 75%. Although no statistical testing was done, and there is no concurrent control group, the dramatic rises in screening temporally associated with implementation of medical assistant screening is strong evidence of a causal relationship.

Lastly, there were 2 systematic reviews with data relevant to this question. The first is a VA Evidence Synthesis Project report by the Durham VA, who assessed the evidence for nurse-managed protocols in outpatient management of adults with chronic conditions.^13^ Although not required to be part of team-based care, this review was nevertheless considered to be relevant for examining the potential use of nurses in team-based care to manage chronic conditions. The review searched computerized databases from 1980 through December 2012 and identified 29 unique studies, 26 of which were RCTs, and all of which compared the nurse-managed protocol to usual care. Most studies were about patients with elevated cardiovascular risk. Only 1 study described interactions of the nurse with the team physician, which would be a sine qua non for team-based care. Thus the assumption that most of what is being assessed is not in the context of team-based care. All 29 studies required the nurse to have autonomy to titrate medications. Twenty studies reported that the nurse was allowed to independently initiate a new medication. Meta-analysis of studies (anywhere from 5 to 12 depending on outcome) showed low- to moderate-certainty evidence that nurse-managed protocols compared to usual care resulted in improvements in measures such as A1c, blood pressure, total and LDL cholesterol, as well as outcomes like total hospitalizations, heart failure hospitalizations, and even mortality.

The other systematic review assessed the associations of interprofessional primary care team characteristics on use of health services and patient outcomes.^14^ The review was published in 2019, but the end date of the computerized database search was not included in the article. Thirty-one quantitative studies were included in the narrative synthesis (along with 38 qualitative studies and 8 mixed-methods studies). The authors’ synthesis states that “the addition of specific professions to teams was generally positively associated with care processes”, and goes on to state that “for example, the addition of nurses or the expansion of their role improved care coordination”, but only cited references, and not abstracted data, is given in support of this statement. Reference mining the cited studies in this review yielded 34 articles that were examined, but none of these met the inclusion criteria for this review; thus, we refrain from accepting at face value the conclusion of this review.

Table 3 Comparative Studies of Adding Team Members

Author, Year | Study Design | Setting | Team Members Added | Outcomes | Results
Basu, 2018^9^ | Model | US internal medicine and family practices seeing fee-for-service patients | 1) Medical scribe; 2) Medical assistants | Costs | In order to be cost-neutral, use of the medical scribe would need to save 3.5 minutes per visit, enabling the physician to see an additional 317 visits per year; the corresponding numbers for the medical assistant strategy is a saving of 7.4 minutes per visit with an increase of 720 visits per year
D’Afflitti, 2018^10^ | Pre-post | General internal medicine practice at Boston Medical Center | NP-physician care team | Access | Decrease in average time to third next available appointment from 26.2 to 6.6 days (statistical testing not done)
Dai, 2019^11^ | Cross-sectional survey; N=11,800 | US family practices | NP/PA | Panel size | Panel size is 245 to 410 patients higher in practices that have an NP or PA or both
Dorr, 2006^15^ | Observational longitudinal with control; N=2,356 treated by care manager team | Intermountain Healthcare | Chronic care manager added to PC team | Diabetes control, costs for depression care | Compared to patients treated without care management, intervention patients had greater decreases in A1c (−0.55% vs −0.18%), lower costs for depression (85 decrease vs 19% increase), and increased primary care productivity (8% vs 5.5%) Statistical testing not performed.
Litaker, 2003^12^ | RCT; N=157 | General internal medicine at Cleveland Clinic | NP trained in chronic disease management added to physician team, vs physician-only care | Diabetes care, hypertension, preventative care, HRQOL | Compared to physician only care, patients treated in the teams with the NP had greater decreases in A1c (0.63 vs 0.15) but no better control of blood pressure. Personnel costs were greater in the NP group.
Stoeckle, 2019^16^ | Time series; N = 12,462 | Family medicine clinic at Thomas Jefferson | Medical assistants who were already team members were trained to provide screening | Screening for depression and falls | Dramatic increases in screening coincident with implementation, from 0% to 64% for depression and from 23% to 75% for falls
Shaw, 2013^13^ | Systematic review of 29 studies, search ended in 2012 | Adult outpatient practice | Nurse, although not required to be team-based | Clinical quality resource use; nursing satisfaction | Compared to usual care, nurse-managed protocols resulted in numerous improvements in intermediate outcomes such as A1c control, blood pressure, and lipids, as well as reductions in hospitalization and mortality.
Wranik, 2019^14^ | Systematic review of 31 quantitative studies | Primary care in Western publicly-funded health care systems focusing on general care, diabetes, asthma, ischemic heart disease, hypertension, and multi-morbidity care | Nurses, pharmacists, non-clinical staff | Clinical process and outcomes | “The addition of specific professions to teams was generally positively associated with care processes”

### Pre-post or time series studies of going from a defined “no team” structure to a defined “team-based” structure

We identified 1 hypothesis-testing study in this category.^17^ This was a description of how Stanford developed and implemented a new model of primary care in 1 of their clinics. The authors describe a careful process that included site visits to other systems noted for high-performing primary care practices, input from patient stakeholders, re-design of the physical space, implementation and evaluation of the new model of care, and more. The new care model had care teams composed of a physician and an advanced practice provider along with 4 medical assistants. Three of these teams were grouped together to care for 10,000 patients, and each of these larger care teams had access to additional onsite expertise, including a clinical pharmacist, dietician, behavioral health specialist, nurse, and physical therapist. In the pilot clinic where this was implemented, the authors reports there were “positive trends” over time, including an increase in the Press-Ganey likelihood-to-recommend proportion from 81.0% to 83.6%, a HEDIS composite measure from 65.8% to 72.3%, and a measure of provider well-being increased from 49 to 64.7. However, no sample sizes or other data are provided to support these numbers, there is no statistical testing to be able to assess whether the 2 numbers are in fact statistically different, and there is no non-intervention control group to assess whether these changes are more or less than temporal trends in satisfaction, HEDIS scores, or provider well-being.