# METHODS

## TOPIC DEVELOPMENT

This topic was developed in response to a nomination by Idamay Curtis, Co-Director of Primary Care Analytics Team, Dr. Karin Nelson, Director of the Office of Primary Care Analytics Team, and Dr. Greg Stewart, Professor of Management and Entrepreneurship. Key questions were then developed with input from the topic nominator, the ESP coordinating center, and the review team.

The initial Key Questions were:

KQ1 Who should be a member of the care team (which occupations)?
KQ2 What roles and responsibilities are needed to provide high-quality, accessible primary care?
KQ3 What extended team members are needed (eg, Certified Diabetes Educators, Certified Pharmacy Specialists, Social Workers)?

After discussions with the topic nominator, the Key Questions were refined by the following:

When VA launched the Patient-Aligned Care Team (PACT) initiative, the team (or teamlet) was defined (based on limited data) as: 1) a provider (physician, nurse practitioner); a full-time RN care manager; 3) a full-time LPN; 4) a full-time clerk. The question then is: is there a better team-based care structure? What roles are needed and how should primary care teams be structured?

This then resulted in the revised Key Question:

KQ: What are the effects of different primary care team structures on care?

The review was not registered in PROSPERO because it was not about an eligible “intervention”.

## SEARCH STRATEGY

We conducted broad searches using terms relating to “patient care team” or “team based” or “primary health care.” We searched OVID Medline from inception to 5/29/20. See Appendix A for complete search strategy.

## STUDY SELECTION

All title, abstract, and ful-text articles were screened by 1 reviewer, Paul G. Shekelle (PGS). Questions about the relevance of an abstract or full-text article were discussed directly with the partner. Studies were included at either the abstract or the full-text level if they were hypothesis-testing studies, modeling studies, or systematic reviews of the following types, in descending order of the degree to which it can inform the key question:

1) A comparative study of 2 different primary care team structures (randomized or observational);
2) A pre-post or time series study of 2 different structures for the same team – in other words at time point zero a team has 1 structure and this is then changed at a later time to a different structure;
3) Hypothesis-testing studies of adding a new team member to an established team – for example, like adding a nurse practitioner or a pharmacist to an existing team;
4) Pre-post or time series studies of going from a “no team” structure to a defined “team-based” structure; or
5) Included studies needed to report a triple aim outcome (quality, cost, patient experience) or provider-based outcome (such as burnout).

We did not include studies that were about implementing “team-based care”, which typically consists of a pre-implementation “usual care” that is not-team based and/or loosely defined, and then a post-implementation assessment of team-based care, with “team-based” being defined by principles but not with the associated specifications of how each team is constituted (in terms of FTE, etc).

We did not include studies from the large literature of adding to the team a new member who deals only with a specific condition – for example, adding a case manager for patients with HIV. We only included such studies of adding a designated new team member if that person had responsibilities for at least 2 different health conditions.

We did not include qualitative studies that examined experiences or beliefs about team-based primary care.

We did not include studies about team-based care in other disciplines (mental health, for example).

“Team” was primarily defined as VA defines a teamlet – a provider, nurse, case manager, clerk, etcetera. A secondary definition of “team” was the team writ large, meaning a collection of primary care providers, nurses, clerks, etcetera, working within an integrated clinic setting.

## DATA ABSTRACTION

Data extraction was completed by author PGS. Data abstracted included the study design, setting, sample size, team members added or team members studied, outcomes, and data needed for the quality assessment/risk of bias tools.

## QUALITY ASSESSMENT

Randomized trials were assessed for quality/risk of bias using the Cochrane Risk of Bias Tool.^2^ Observational studies that were longitudinal and had a control group were assessed using the Cochrane Risk of Bias in Observational Studies – interventions (ROBINS-I).^3^ Cross-sectional and pre-post studies were not assessed for risk of bias with a tool since they are by definition at high risk of bias. Modeling studies were not assessed for quality because no standardized tool exists for that purpose.

## DATA SYNTHESIS

We grouped studies into 1 of the 4 categories described above, and within category summarized the evidence narratively.

## RATING THE BODY OF EVIDENCE

We used the criteria of the Grading of Recommendations Assessment, Development and Evaluation (GRADE) working group.^4^ GRADE assesses the certainty of the evidence based on the assessment of the following domains: risk of bias, imprecision, inconsistency, indirectness, and publication bias. This results in categories as follows:

- High: We are very confident that the true effect lies close to that of the estimate of the effect.
- Moderate: We are moderately confident in the effect estimate. The true effect is likely to be close to the estimate of the effect, but there is a possibility that it is substantially different.
- Low: Our confidence in the effect estimate is limited. The true effect may be substantially different from the estimate of the effect.
- Very low/Insufficient: We have very little confidence in the effect estimate. The true effect is likely to be substantially different from the estimate of effect.

## PEER REVIEW

A draft version of the report was reviewed by technical experts and clinical leadership. Peer reviewer comments and responses are included in Appendix B.