# APPENDIX D RISK OF BIAS TOOL

## Risk of Bias Assessment for Included RCT

Author, year | Random sequence generation | Allocation concealment | Blinding of participants and personnel | Blinding of outcome assessment | Incomplete outcome data | Selective reporting
Litaker, 2003^12^ | Unknown | Unknown | High risk | High risk | Low risk | Low risk

## Risk of Bias for Included Observation Studies with Control

Author, year | Confounding | Selection bias | Bias in measurement classification of interventions | Bias due to deviations from intended interventions | Bias due to missing data | Bias in measurement of outcomes | Bias in selection of reported results
Ohved, 2000^8^ | High risk | Low risk | Low risk | Low risk | Low risk | Low risk | Low risk
Dorr, 2006^15^ | High risk | Low risk | Low risk | Low risk | Low risk | Low risk | Low risk