# APPENDIX C CITATIONS FOR EXCLUDED PUBLICATIONS

## Abstract Excludes

### Not Research (n=27)

1 Arevian, M., The significance of a collaborative practice model in delivering care to chronically ill patients: a case study of managing diabetes mellitus in a primary health care center. Journal of Interprofessional Care, 2005. 19(5): p. 444–51.16308168
2 Badger, L.W., ., The case for integration of social work psychosocial services into rural primary care practice. Health & Social Work, 1997. 22(1): p. 20–9.9021415
3 Bodenheimer, T. and B.Y. Laing, The teamlet model of primary care. Annals of Family Medicine, 2007. 5(5): p. 457–61.17893389
4 Bodenheimer, T. and R. Willard-Grace, Teamlets in Primary Care: Enhancing the Patient and Clinician Experience. Journal of the American Board of Family Medicine: JABFM, 2016. 29(1): p. 135–8.26769885
5 Campbell, J.G. and A. Richard-Eaglin, Implementing an Integrated Team-Based Model of Care. North Carolina Medical Journal, 2018. 79(4): p. 228–229.29991613
6 Corso, K.A. and D. Gage, Nurses and Psychologists Advancing the Patient-Centered Medical Home Model. Nursing Administration Quarterly, 2016. 40(3): p. 192–201.27259123
7 Dahl-Popolizio, S., ., Enhancing the value of integrated primary care: The role of occupational therapy. Families, Systems, & Health, 2016. 34(3): p. 270–80.
8 Falloon, D., The social worker. A member of the primary care team? West Indian Medical Journal, 1998. 47 Suppl 4: p. 28–30.
9 Fiscella, K. and S.H. McDaniel, The complexity, diversity, and science of primary care teams. American Psychologist, 2018. 73(4): p. 451–467.
10 Freund, T., ., Skill mix, roles and remuneration in the primary care workforce: who are the healthcare professionals in the primary care teams across the world? International Journal of Nursing Studies, 2015. 52(3): p. 727–43.25577306
11 Hahn, N. and W. Weart, The pharmacist’s role in the optimal delivery of primary care in a managed care world. Pharmacy Practice Management Quarterly, 1996. 15(4): p. 36–43.10153843
12 Jortberg, B.T. and M.O. Fleming, Registered dietitian nutritionists bring value to emerging health care delivery models. Journal of the Academy of Nutrition & Dietetics, 2014. 114(12): p. 2017–22.25458750
13 Leasure, E.L., ., There is no “i” in teamwork in the patient-centered medical home: defining teamwork competencies for academic practice. Academic Medicine, 2013. 88(5): p. 585–92.23524923
14 Moore, T., ., Increasing access to care using clinical pharmacy specialist providers in outpatient mental health: Successful practice integration within the Department of Veterans Affairs. Journal of the American Pharmacists Association: JAPhA, 2020. 09: p. 09.
15 Nigro, S.C., ., Clinical pharmacists as key members of the patient-centered medical home: an opinion statement of the Ambulatory Care Practice and Research Network of the American College of Clinical Pharmacy. Pharmacotherapy:The Journal of Human Pharmacology & Drug Therapy, 2014. 34(1): p. 96–108.
16 O’Connor, P.J., L.I. Solberg, and M. Baird, The future of primary care. The enhanced primary care model. Journal of Family Practice, 1998. 47(1): p. 62–7.
17 Patterson, E., H. Muenchberger, and E. Kendall, The role of practice nurses in coordinated care of people with chronic and complex conditions. Australian Health Review, 2007. 31(2): p. 231–8.17470044
18 Price, E., ., Organisation of services for people with cardiovascular disorders in primary care: transfer to primary care or to specialist-generalist multidisciplinary teams? BMC Family Practice, 2014. 15: p. 158.25245456
19 Raju, A., ., The expanding role of Minnesota pharmacists in primary care. Minnesota Medicine, 2011. 94(10): p. 49–51.
20 Reckrey, J.M., ., The critical role of social workers in home-based primary care. Social Work in Health Care, 2014. 53(4): p. 330–43.24717182
21 Smith, M., ., Why pharmacists belong in the medical home. Health Affairs, 2010. 29(5): p. 906–13.20439879
22 Smith, M., D.W. Bates, and T.S. Bodenheimer, Pharmacists belong in accountable care organizations and integrated care teams. Health Affairs, 2013. 32(11): p. 1963–70.24191087
23 Soan, E.J., ., Exercise physiologists: essential players in interdisciplinary teams for noncommunicable chronic disease management. Journal of multidisciplinary healthcare, 2014. 7: p. 65–8.24511238
24 Stephens, L., Family nurse practitioners: “value add” in outpatient chronic disease management. Primary Care; Clinics in Office Practice, 2012. 39(4): p. 595–603.23148952
25 Taylor, E.F., ., Enhancing the primary care team to provide redesigned care: the roles of practice facilitators and care managers. Annals of Family Medicine, 2013. 11(1): p. 80–3.23319510
26 Vrijhoef, H.J., ., The nurse specialist as main care-provider for patients with type 2 diabetes in a primary care setting: effects on patient outcomes. International Journal of Nursing Studies, 2002. 39(4): p. 441–51.11909620
27 Yang, Y.T. and M.R. Meiners, Care Coordination and the Expansion of Nursing Scopes of Practice. Journal of Law, Medicine & Ethics, 2014. 42(1): p. 93–103.

### Not about Specific Team Member Roles in TBPC (n=24)

1 Annis, A.M., ., Trends in primary care encounters across professional roles in PCMH. American Journal of Managed Care, 2018. 24(7): p. e222–e229.
2 Blumenthal, K.J., A.T. Chien, and S.J. Singer, Relationship among team dynamics, care coordination and perception of safety culture in primary care. Family Practice, 2018. 35(6): p. 718–723.29788350
3 Diop, M., ., Does enrollment in multidisciplinary team-based primary care practice improve adherence to guideline-recommended processes of care? Quebec’s Family Medicine Groups, 2002-2010. Health Policy, 2017. 121(4): p. 378–388.28233598
4 Engels, Y., ., The effects of a team-based continuous quality improvement intervention on the management of primary care: a randomised controlled trial. British Journal of General Practice, 2006. 56(531): p. 781–7.
5 Giannitrapani, K.F., ., Role expansion on interprofessional primary care teams: Barriers of role self-efficacy among clinical associates. Healthcare, 2016. 4(4): p. 321–326.28007226
6 Grol, S.M., ., The role of the general practitioner in multidisciplinary teams: a qualitative study in elderly care. BMC Family Practice, 2018. 19(1): p. 40.29523092
7 Hall, T.L., ., Understanding adaptations to patient-centered medical home activities: The PCMH adaptations model. Translational Behavioral Medicine, 2017. 7(4): p. 861–872.28620725
8 Henschen, B.L., ., Four-Year Educational and Patient Care Outcomes of a Team-Based Primary Care Longitudinal Clerkship. Academic Medicine, 2015. 90(11 Suppl): p. S43–9.26505100
9 Hung, D.Y., ., Experiences of primary care physicians and staff following lean workflow redesign. BMC Health Services Research, 2018. 18(1): p. 274.29636052
10 Jones, S.M.W., ., Measuring attributes of team functioning in primary care settings: development of the TEAMS tool. Journal of Interprofessional Care, 2020. 34(3): p. 407–413.31573363
11 Kayingo, G., ., Primary Care Teams, Composition, Roles, and Satisfaction of PA Students During Primary Care Rotations. The Journal of Physician Assistant Education, 2015. 26(2): p. 88–92.26211031
12 Laberge, M., ., Costs of health care across primary care models in Ontario. BMC Health Services Research, 2017. 17(1): p. 511.28764776
13 Laberge, M., ., Hospitalizations for ambulatory care sensitive conditions across primary care models in Ontario, Canada. Social Science & Medicine, 2017. 181: p. 24–33.28365547
14 Ladebue, A.C., ., The experience of Patient Aligned Care Team (PACT) members. Health Care Management Review, 2016. 41(1): p. 2–10.25539056
15 Levesque, J.F., ., Dimensions and intensity of inter-professional teamwork in primary care: evidence from 5 international jurisdictions. Family Practice, 2018. 35(3): p. 285–294.29069391
16 Meo, N., ., Elements of the Veterans Health Administration Patient-Centered Medical Home are Associated with Greater Adherence to Oral Hypoglycemic Agents in Patients with Diabetes. Population Health Management, 2018. 21(2): p. 116–122.28677990
17 Miller, R., C. Weir, and S. Gulati, Transforming primary care: scoping review of research and practice. Journal of Integrated Care, 2018. 26(3): p. 176–188.30166943
18 Panattoni, L., ., Cost Estimates for Designing and Implementing a Novel Team Care Model for Chronically Ill Patients. Journal of Ambulatory Care Management, 2018. 41(1): p. 58–70.
19 Reiss-Brennan, B., ., Association of Integrated Team-Based Care With Health Care Quality, Utilization, and Cost. JAMA, 2016. 316(8): p. 826–34.27552616
20 Rijken, M., ., Managing multimorbidity: Profiles of integrated care approaches targeting people with multiple chronic conditions in Europe. Health Policy, 2018. 122(1): p. 44–52.29102089
21 Riverin, B.D., ., Team-based versus traditional primary care models and short-term outcomes after hospital discharge. CMAJ Canadian Medical Association Journal, 2017. 189(16): p. E585–E593.28438951
22 Sullivan, J.L., ., Implementation of the Geriatric Patient-Aligned Care Team Model in the Veterans Health Administration (VA). Journal of the American Board of Family Medicine: JABFM, 2018. 31(3): p. 456–465.29743228
23 van Eeghen, C.O., B. Littenberg, and R. Kessler, Chronic care coordination by integrating care through a team-based, population-driven approach: a case study. Translational Behavioral Medicine, 2018. 8(3): p. 468–480.29800398
24 Von Korff, M., ., Functional outcomes of multi-condition collaborative care and successful ageing: results of randomised trial. BMJ, 2011. 343: p. d6612.22074851

### Adding Pharmacists (n=22)

1 Borenstein, J.E., ., Physician-pharmacist comanagement of hypertension: a randomized, comparative trial. Pharmacotherapy:The Journal of Human Pharmacology & Drug Therapy, 2003. 23(2): p. 209–16.
2 Carter, B.L., ., A cluster-randomized effectiveness trial of a physician-pharmacist collaborative model to improve blood pressure control. Circulation. Cardiovascular Quality & Outcomes, 2010. 3(4): p. 418–23.20647575
3 Chandler, C., ., Pharmacists on a primary care team at a Veterans Affairs medical center. American Journal of Health-System Pharmacy, 1997. 54(11): p. 1280–7.9179348
4 Freeman, C., ., Does a primary care practice pharmacist improve the timeliness and completion of medication management reviews? International Journal of Pharmacy Practice, 2012. 20(6): p. 395–401.
5 Funk, K.A. and K.K. Weaver, Team work and collaborative practice agreements among pharmacists and nurse practitioners. Journal of the American Pharmacists Association: JAPhA, 2018. 58(1): p. 117–119.29217143
6 Gentry, C.K., ., Integration of Clinical Pharmacist Services into an Underserved Primary Care Clinic Utilizing an Interprofessional Collaborative Practice Model. Journal of Health Care for the Poor & Underserved, 2016. 27(1): p. 1–7.
7 Giannitrapani, K.F., ., Expanding the role of clinical pharmacists on interdisciplinary primary care teams for chronic pain and opioid management. BMC Family Practice, 2018. 19(1): p. 107.29970008
8 Gilani, F., ., Adding pharmacists to primary care teams increases guideline-concordant antiplatelet use in patients with type 2 diabetes: results from a randomized trial. Annals of Pharmacotherapy, 2013. 47(1): p. 43–8.
9 Hazen, A.C.M., ., The degree of integration of non-dispensing pharmacists in primary care practice and the impact on health outcomes: A systematic review. Research In Social & Administrative Pharmacy, 2018. 14(3): p. 228–240.28506574
10 Hirsch, J.D., ., Primary care-based, pharmacist-physician collaborative medication-therapy management of hypertension: a randomized, pragmatic trial. Clinical Therapeutics, 2014. 36(9): p. 1244–54.25085406
11 Ip, E.J., ., Enhancing diabetes care by adding a pharmacist to the primary care team. American Journal of Health-System Pharmacy, 2013. 70(10): p. 877–86.23640349
12 Jorgenson, D., ., Integrating pharmacists into primary care teams: barriers and facilitators. International Journal of Pharmacy Practice, 2014. 22(4): p. 292–9.
13 Joseph, T., ., Integration Strategies of Pharmacists in Primary Care-Based Accountable Care Organizations: A Report from the Accountable Care Organization Research Network, Services, and Education. Journal of Managed Care & Specialty Pharmacy, 2017. 23(5): p. 541–548.28448780
14 Kennelty, K.A., L.A. Polgreen, and B.L. Carter, Team-Based Care with Pharmacists to Improve Blood Pressure: a Review of Recent Literature. Current Hypertension Reports, 2018. 20(1): p. 1.29349522
15 Kolodziejak, L., A. Remillard, and S. Neubauer, Integration of a primary healthcare pharmacist. Journal of Interprofessional Care, 2010. 24(3): p. 274–84.20388026
16 McFarland, M.S., ., Perceptions of Integration of the Clinical Pharmacist into the Patient Care Medical Home Model. Journal for Healthcare Quality, 2018. 40(5): p. 265–273.29280778
17 Moreno, G., ., Physician experiences with clinical pharmacists in primary care teams. Journal of the American Pharmacists Association: JAPhA, 2017. 57(6): p. 686–691.28811089
18 Scott, M.A., ., Integration of pharmacists into a patient-centered medical home. Journal of the American Pharmacists Association: JAPhA, 2011. 51(2): p. 161–6.21382805
19 Shulman, J.I., S. Shulman, and A.P. Haines, The prevention of adverse drug reactions--a potential role for pharmacists in the primary care team? Journal of the Royal College of General Practitioners, 1981. 31(228): p. 429–34.
20 Smith, M.A., Implementing primary care pharmacist services: Go upstream in the world of value-based payment models. Research In Social & Administrative Pharmacy, 2017. 13(5): p. 892–895.28214149
21 St Peter, W.L., T.M. Farley, and B.L. Carter, Role of collaborative care models including pharmacists in improving blood pressure management in chronic kidney disease patients. Current Opinion in Nephrology & Hypertension, 2011. 20(5): p. 498–503.21709550
22 Tan, E.C., ., Pharmacist services provided in general practice clinics: a systematic review and meta-analysis. Research In Social & Administrative Pharmacy, 2014. 10(4): p. 608–22.24161491

### Not about Team-based Primary Care (n=22)

1 Bailey, J.E., ., Effect of Intensive Interdisciplinary Transitional Care for High-Need, High-Cost Patients on Quality, Outcomes, and Costs: a Quasi-Experimental Study. Journal of General Internal Medicine, 2019. 34(9): p. 1815–1824.31270786
2 Bauer, M.S., ., Effectiveness of Implementing a Collaborative Chronic Care Model for Clinician Teams on Patient Outcomes and Health Status in Mental Health: A Randomized Clinical Trial. JAMA Network Open, 2019. 2(3): p. e190230.30821830
3 Butler, M., ., Does integrated care improve treatment for depression? A systematic review. Journal of Ambulatory Care Management, 2011. 34(2): p. 113–25.
4 Callahan, C.M., ., Effectiveness of collaborative care for older adults with Alzheimer disease in primary care: a randomized controlled trial. JAMA, 2006. 295(18): p. 2148–57.16684985
5 Cohen, D., ., A practice change model for quality improvement in primary care practice. Journal of Healthcare Management, 2004. 49(3): p. 155–68; discussion 169-70.15190858
6 Crabtree, B.F., ., Leading Innovative Practice: Leadership Attributes in LEAP Practices. Milbank Quarterly, 2020. 13: p. 13.
7 DiCenso, A., ., Utilization of nurse practitioners to increase patient access to primary healthcare in Canada--thinking outside the box. Nursing leadership (Toronto, Ont.), 2010. 23 Spec No 2010: p. 239–59.
8 Gary, T.L., ., The effects of a nurse case manager and a community health worker team on diabetic control, emergency department visits, and hospitalizations among urban African Americans with type 2 diabetes mellitus: a randomized controlled trial. Archives of Internal Medicine, 2009. 169(19): p. 1788–94.19858437
9 Gilbody, S., ., Collaborative care for depression: a cumulative meta-analysis and review of longer-term outcomes. Archives of Internal Medicine, 2006. 166(21): p. 2314–21.17130383
10 Henschen, B.L., ., Continuity With Patients, Preceptors, and Peers Improves Primary Care Training: A Randomized Medical Education Trial. Academic Medicine, 2020. 95(3): p. 425–434.31626000
11 Kilpatrick, K., ., Implementing primary healthcare nurse practitioners in long-term care teams: A qualitative descriptive study. Journal of Advanced Nursing, 2019. 75(6): p. 1306–1315.30697772
12 Lineker, S.C., J.A. Husted, and K.S. Brown, Influence of discipline of provider and model of care on an arthritis educational intervention in primary care. Arthritis care & research, 2012. 64(3): p. 424–33.22076836
13 McCleery, E., ., Evidence Brief: The Quality of Care Provided by Advanced Practice Nurses. Department of Veterans Affairs, 2011.
14 Moe, G.C., J.E.S. Moe, and A.L. Bailey, Evaluating the implementation of collaborative teams in community family practice using the Primary Care Assessment Tool. Canadian Family Physician, 2019. 65(12): p. e515–e522.31831500
15 Pohl, J.M., ., Analysis & commentary. Unleashing nurse practitioners’ potential to deliver primary care and lead teams. Health Affairs, 2010. 29(5): p. 900–5.20439878
16 Prasad, S., ., Rural geriatric glue: a nurse practitioner-led model of care for enhancing primary care for frail older adults within an ecosystem approach. Journal of the American Geriatrics Society, 2014. 62(9): p. 1772–80.25243682
17 Sharpe, M., ., Integrated collaborative care for comorbid major depression in patients with cancer (SMaRT Oncology-2): a multicentre randomised controlled effectiveness trial. Lancet, 2014. 384(9948): p. 1099–108.25175478
18 Shea, C.M., ., Contextual factors that influence quality improvement implementation in primary care: The role of organizations, teams, and individuals. Health Care Management Review, 2018. 43(3): p. 261–269.29533271
19 Swindle, R.W., ., Integrating clinical nurse specialists into the treatment of primary care patients with depression. International Journal of Psychiatry in Medicine, 2003. 33(1): p. 17–37.12906341
20 Viswanathan, M., ., Agency for Healthcare Research and Quality, 2014: p. 03.
21 Walker, J., ., Integrated collaborative care for major depression comorbid with a poor prognosis cancer (SMaRT Oncology-3): a multicentre randomised controlled trial in patients with lung cancer. Lancet Oncology, 2014. 15(10): p. 1168–76.25175097
22 Way, D., ., Primary health care services provided by nurse practitioners and family physicians in shared practice. CMAJ Canadian Medical Association Journal, 2001. 165(9): p. 1210–4.11706910

### Qualitative Study (n=17)

1 Benzer, J.K., ., Team Process Variation Across Diabetes Quality of Care Trajectories. Medical Care Research & Review, 2016. 73(5): p. 565–89.26670549
2 Brant, C. and G.M. Leydon, The role of the health-care assistant in general practice. British Journal of Nursing, 2009. 18(15): p. 926, 928–30, 932–3.19717991
3 Brown-Johnson, C., ., Role definition is key-Rapid qualitative ethnography findings from a team-based primary care transformation. Learning Health Systems, 2019. 3(3): p. e10188.31317071
4 Contandriopoulos, D., ., A process-based framework to guide nurse practitioners integration into primary healthcare teams: results from a logic analysis. BMC Health Services Research, 2015. 15: p. 78.25889415
5 Ferrante, J.M., ., Barriers and Facilitators to Expanding Roles of Medical Assistants in Patient-Centered Medical Homes (PCMHs). Journal of the American Board of Family Medicine: JABFM, 2018. 31(2): p. 226–235.29535239
6 Goldman, R.E., ., What matters in patient-centered medical home transformation: Whole system evaluation outcomes of the Brown Primary Care Transformation Initiative. SAGE Open Medicine, 2018. 6: p. 2050312118781936.29977548
7 Grace, S.M., ., Flexible implementation and integration of new team members to support patient-centered care. Healthcare, 2014. 2(2): p. 145–51.26250383
8 Lane, R., ., When colocation is not enough: a case study of General Practitioner Super Clinics in Australia. Australian Journal of Primary Health, 2017. 23(2): p. 107–113.28442054
9 Lovink, M.H., ., Skill mix change between general practitioners, nurse practitioners, physician assistants and nurses in primary healthcare for older people: a qualitative study. BMC Family Practice, 2018. 19(1): p. 51.29720099
10 MacNaughton, K., S. Chreim, and I.L. Bourgeault, Role construction and boundaries in interprofessional primary health care teams: a qualitative study. BMC Health Services Research, 2013. 13: p. 486.24267663
11 Maharaj, S., ., Integrating Physiotherapists into Primary Health Care Organizations: The Physiotherapists’ Perspective. Physiotherapy Canada, 2018. 70(2): p. 188–195.29755175
12 Mills, J., ., Australian nurses in general practice, enabling the provision of cervical screening and well women’s health care services: a qualitative study. BMC Nursing, 2012. 11: p. 23.23145901
13 Reinschmidt, K.M., ., Documenting Community Health Worker Roles in Primary Care: Contributions to Evidence-Based Integration Into Health Care Teams, 2015. Journal of Ambulatory Care Management, 2017. 40(4): p. 305–315.
14 Rodriguez, H.P., ., Teamlet structure and early experiences of medical home implementation for veterans. Journal of General Internal Medicine, 2014. 29 Suppl 2: p. S623–31.24715392
15 Sheridan, B., ., Team-based primary care: The medical assistant perspective. Health Care Management Review, 2018. 43(2): p. 115–125.27849646
16 Solimeo, S.L., G.L. Stewart, and G.E. Rosenthal, The Critical Role of Clerks in the Patient-Centered Medical Home. Annals of Family Medicine, 2016. 14(4): p. 377–9.27401428
17 Souza, M.B., ., [Teamwork in primary care: the experience of Portugal]. Pan American Journal of Public Health, 2013. 33(3): p. 190–5.23698138

### No Relevant Outcomes (n=8)

1 Burgess, J., A. Martin, and W. Senner, A framework to assess nurse practitioner role integration in primary health care. Canadian Journal of Nursing Research, 2011. 43(1): p. 22–40.
2 Eccles, M.P., ., Improving the delivery of care for patients with diabetes through understanding optimised team work and organisation in primary care. Implementation Science, 2009. 4: p. 22.19397796
3 Frogner, B.K., C.R. Snyder, and J.R. Hornecker, Examining the Healthcare Administrator’s Perspective on “Teamness” in Primary Care. Journal of Healthcare Management, 2018. 63(6): p. 397–408.30418368
4 Pereira, V., M.H. Gabriel, and L. Unruh, Multiyear Performance Trends Analysis of Primary Care Practices Demonstrating Patient-Centered Medical Home Transformation: An Observation of Quality Improvement Indicators among Outpatient Clinics. American Journal of Medical Quality, 2019. 34(2): p. 109–118.30101596
5 Quinlan, E. and S. Robertson, The communicative power of nurse practitioners in multidisciplinary primary healthcare teams. Journal of the American Association of Nurse Practitioners, 2013. 25(2): p. 91–102.23347245
6 Sangster-Gormley, E., ., Factors affecting nurse practitioner role implementation in Canadian practice settings: an integrative review. Journal of Advanced Nursing, 2011. 67(6): p. 1178–90.21261696
7 Torrens, C., ., Barriers and facilitators to the implementation of the advanced nurse practitioner role in primary care settings: A scoping review. International Journal of Nursing Studies, 2020. 104: p. 103443.32120089
8 Valaitis, R., ., Examining Interprofessional teams structures and processes in the implementation of a primary care intervention (Health TAPESTRY) for older adults using normalization process theory. BMC Family Practice, 2020. 21(1): p. 63.32295524

### No Abstract (n=6)

1 Baker, K., An Emerging Role for RN’s: the RN Primary Care Coordinator. Oklahoma Nurse, 2015. 60(3): p. 13–4.
2 Funk, K.A. and M. Davis, Enhancing the Role of the Nurse in Primary Care: The RN “Co-Visit” Model. Journal of General Internal Medicine, 2015. 30(12): p. 1871–3.26194640
3 Iglehart, J.K., Expanding the role of advanced nurse practitioners--risks and rewards. New England Journal of Medicine, 2013. 368(20): p. 1935–41.
4 Kong, M., Capsule Commentary on Misra-Hebert ., Implementing Team-Based Primary Care Models: A Mixed-Methods Comparative Case Study in a Large, Integrated Health Care System. Journal of General Internal Medicine, 2018. 33(11): p. 1958.30203356
5 Muir, S., Occupational therapy in primary health care: we should be there. American Journal of Occupational Therapy, 2012. 66(5): p. 506–10.
6 Warde, C.M., K.F. Giannitrapani, and M.L. Pearson, Teaching primary care teamwork: a conceptual model of primary care team performance. The clinical teacher, 2020. 17(3): p. 249–254.31282077

### Adding Occupational Therapists (n=1)

1 Donnelly, C., ., The integration of occupational therapy into primary care: a multiple case study design. BMC Family Practice, 2013. 14: p. 60.23679667

### Descriptive Study (n=1)

1 Xue, Y., ., Trends in Primary Care Provision to Medicare Beneficiaries by Physicians, Nurse Practitioners, or Physician Assistants: 2008-2014. Journal of Primary Care & Community Health, 2017. 8(4): p. 256–263.

### Study Protocol (n=1)

1 Hysong, S.J., ., Impact of team configuration and team stability on primary care quality. Implementation Science, 2019. 14(1): p. 22.30841926

## Full Text Excludes

### Not about Specific Team Member Roles in TBPC (n=32)

1 Annis, A.M., ., Do Patient-Centered Medical Home Access and Care Coordination Measures Reflect the Contribution of All Team Members? A Systematic Review. Journal of Nursing Care Quality, 2016. 31(4): p. 357–66.27219827
2 Baxter, S., ., The effects of integrated care: a systematic review of UK and international evidence. BMC Health Services Research, 2018. 18(1): p. 350.29747651
3 Black, D.A., ., The Teamwork Study: enhancing the role of non-GP staff in chronic disease management in general practice. Australian Journal of Primary Health, 2013. 19(3): p. 184–9.22951281
4 Bonciani, M., S. Barsanti, and A.M. Murante, Is the co-location of GPs in primary care centres associated with a higher patient satisfaction? Evidence from a population survey in Italy. BMC Health Services Research, 2017. 17(1): p. 248.28376886
5 Carey, T.S., ., Future Research Needs for the Integration of Mental Health/Substance Abuse and Primary Care: Identification of Future Research Needs from Evidence Report/Technology Assessment No. 173. Agency for Healthcare Research and Quality, 2010: p. 09.
6 Fortuna, R.J., ., Impact of Patient-Centered Medical Home Transformation on Providers, Staff, and Quality. Population Health Management, 2020. 25: p. 25.
7 Giannitrapani, K.F., ., Interprofessional training and team function in patient-centred medical home: Findings from a mixed method study of interdisciplinary provider perspectives. Journal of Interprofessional Care, 2018. 32(6): p. 735–744.30156933
8 Harper, P.G., ., Team-based care: an expanded medical assistant role - enhanced rooming and visit assistance. Journal of Interprofessional Care, 2018: p. 1–7.
9 Haverhals, L.M., ., Dedicated to the Mission: Strategies US Department of Veterans Affairs Home-Based Primary Care Teams Apply to Keep Veterans at Home. Journal of the American Geriatrics Society, 2019. 67(12): p. 2511–2518.31593296
10 Helfrich, C.D., ., Association of medical home team-based care functions and perceived improvements in patient-centered care at VHA primary care clinics. Healthcare, 2014. 2(4): p. 238–44.26250630
11 Huang, P.T., ., Impact of family physician integrated care program on decreasing utilization of emergency department visit and hospital admission: a population-based retrospective cohort study. BMC Health Services Research, 2020. 20(1): p. 470.32456640
12 Huber, T.P., H.P. Rodriguez, and S.M. Shortell, The influence of leadership facilitation on relational coordination among primary care team members of accountable care organizations. Health Care Management Review, 2019. 22: p. 22.
13 Husdal R, Rosenblad A, Leksell J, Eliasson B, Jansson S, Jerden L, . Resources and organisation in primary health care are associated with HbA_1c_ level: A nationwide study of 230958 people with Type 2 diabetes mellitus. Prim Care Diabetes. 2018;12(1):23–33. doi: 10.1016/j.pcd.2017.09.003. PubMed PMID: 28964673.28964673
14 Jackson, G.L., ., The patient centered medical home. A systematic review. Annals of Internal Medicine, 2013. 158(3): p. 169–78.24779044
15 Klemenc-Ketis, Z. and A. Poplas-Susic, Are characteristics of team members important for quality management of chronic patients at primary care level? Journal of Clinical Nursing, 2017. 26(23–24): p. 5025–5032.28793377
16 Landrey, A.R., ., Utilization Outcomes of a Pilot Primary Care Team Redesign. Health Services Research & Managerial Epidemiology, 2018. 5: p. 2333392818789844.30202774
17 Manns, B.J., ., Enrolment in primary care networks: impact on outcomes and processes of care for patients with diabetes. CMAJ Canadian Medical Association Journal, 2012. 184(2): p. E144–52.22143232
18 McIntosh, D., L.F. Startsman, and S. Perraud, Mini Review of Integrated Care and Implications for Advanced Practice Nurse Role. The Open Nursing Journal, 2016. 10: p. 78–89.27347258
19 Meyers, D.J., ., Association of Team-Based Primary Care With Health Care Utilization and Costs Among Chronically Ill Patients. JAMA Internal Medicine, 2019. 179(1): p. 54–61.30476951
20 Miedema, B., ., Do new and traditional models of primary care differ with regard to access?: Canadian QUALICOPC study. Canadian Family Physician, 2016. 62(1): p. 54–61.27331231
21 Mitchell, G.K., ., Systematic review of integrated models of health care delivered at the primary-secondary interface: how effective is it and what determines effectiveness? Australian Journal of Primary Health, 2015. 21(4): p. 391–408.26329878
22 Peterson, K., ., Evidence Brief: Effectiveness of Intensive Primary Care Programs. Department of Veterans Affairs, 2011.
23 Poghosyan, L., ., Physician-Nurse Practitioner Teamwork in Primary Care Practices in New York: A Cross-Sectional Survey. Journal of General Internal Medicine, 2020. 35(4): p. 1021–1028.31907791
24 Proia, K.K., ., Team-based care and improved blood pressure control: a community guide systematic review. American Journal of Preventive Medicine, 2014. 47(1): p. 86–99.24933494
25 Riverin, B.D., ., Team-based innovations in primary care delivery in Quebec and timely physician follow-up after hospital discharge: a population-based cohort study. CMAJ open, 2017. 5(1): p. E28–E35.
26 Rosland, A.M., ., Patient-Centered Medical Home Implementation and Improved Chronic Disease Quality: A Longitudinal Observational Study. Health Services Research, 2018. 53(4): p. 2503–2522.29154464
27 Rumball-Smith, J., ., Under the same roof: co-location of practitioners within primary care is associated with specialized chronic care management. BMC Family Practice, 2014. 15: p. 149.25183554
28 Segal, L. and M.J. Leach, An evidence-based health workforce model for primary and community care. Implementation Science, 2011. 6: p. 93.21819608
29 Stroebel RJ, Broers JK, Houle SK, Scott CG, Naessens JM. Improving hypertension control: a team approach in a primary care setting. Jt Comm J Qual Improv. 2000;26(11):623–32. PubMed PMID: 11098425.11098425
30 Stroebel, R.J., ., The impact of clinic design on teamwork development in primary care. Health Care Management Review, 2019. 01: p. 01.
31 Willard-Grace, R., ., Team structure and culture are associated with lower burnout in primary care. Journal of the American Board of Family Medicine: JABFM, 2014. 27(2): p. 229–38.24610185
32 Zijl, A.L.V., ., Interprofessional teamwork in primary care: the effect of functional heterogeneity on performance and the role of leadership. Journal of Interprofessional Care, 2020: p. 1–11.

### Not about Team-based Primary Care (n=10)

1 Callaghan K, Martin-Misener R, O’Connell C, Burge F, Marshall EG. Comparison of Access to Nurse Practitioners in Primary Healthcare across 3 Team Structures. Nurs Leadersh (Tor Ont). 2017;30(4):67–79. doi: 10.12927/cjnl.2017.25447. PubMed PMID: 29676992.29676992
2 Contandriopoulos, D., ., Nurse practitioners, canaries in the mine of primary care reform. Health Policy, 2016. 120(6): p. 682–9.27085958
3 Everett CM, Morgan P, Jackson GL. Primary care physician assistant and advance practice nurses roles: Patient healthcare utilization, unmet need, and satisfaction. Healthc (Amst). 2016;4(4):327–33. doi: 10.1016/j.hjdsi.2016.03.005. PubMed PMID: 27451337.27451337
4 Fiset-Laniel J, Diop M, Provost S, Strumpf EC. The Impact of Team-Based Primary Care on Guideline-Recommended Disease Screening. Am J Prev Med. 2020;58(3):407–17. doi: 10.1016/j.amepre.2019.10.019. PubMed PMID: 31952941.31952941
5 Hobson, A. and A. Curtis, Improving the care of veterans: The role of nurse practitioners in team-based population health management. Journal of the American Association of Nurse Practitioners, 2017. 29(11): p. 644–650.28857487
6 Kadehjian, E.K., ., Challenges to implementing expanded team models: lessons from a centralised nurse-led cholesterol-lowering programme. BMJ Quality & Safety, 2014. 23(4): p. 338–45.
7 Kearns, P., Diabetes Care Management Teams Did Not Reduce Utilization When Compared With Traditional Care: A Randomized Cluster Trial. Managed Care, 2017. 26(10): p. 33–40.
8 Norby, S.M., R.J. Stroebel, and V.J. Canzanello, Physician-nurse team approaches to improve blood pressure control. Journal of Clinical Hypertension, 2003. 5(6): p. 386–92.14688493
9 Ohman-Strickland, P.A., ., Quality of diabetes care in family medicine practices: influence of nurse-practitioners and physician’s assistants. Annals of Family Medicine, 2008. 6(1): p. 14–22.18195310
10 Smith, A.A., D. Kepka, and K.R. Yabroff, Advanced practice registered nurses, physician assistants and cancer prevention and screening: a systematic review. BMC Health Services Research, 2014. 14: p. 68.24521264

### Adding Pharmacists (n=8)

1 Carter, B.L., ., The potency of team-based care interventions for hypertension: a meta-analysis. Archives of Internal Medicine, 2009. 169(19): p. 1748–55.19858431
2 Dennis, S., ., What evidence is there to support skill mix changes between GPs, pharmacists and practice nurses in the care of elderly people living in the community? Australia & New Zealand Health Policy, 2009. 6: p. 23.19744350
3 Mino-Leon, D., H. Reyes-Morales, and S. Flores-Hernandez, Effectiveness of involving pharmacists in the process of ambulatory health care to improve drug treatment adherence and disease control. Journal of Evaluation in Clinical Practice, 2015. 21(1): p. 7–12.24953287
4 O’Neill, J.L., ., Collaborative hypertension case management by registered nurses and clinical pharmacy specialists within the Patient Aligned Care Teams (PACT) model. Journal of General Internal Medicine, 2014. 29 Suppl 2: p. S675–81.24715403
5 Santschi, V., ., Improving blood pressure control through pharmacist interventions: a meta-analysis of randomized controlled trials. Journal of the American Heart Association, 2014. 3(2): p. e000718.24721801
6 Schofield, D., M.M. Cunich, and L. Naccarella, An evaluation of the quality of evidence underpinning diabetes management models: a review of the literature. Australian Health Review, 2014. 38(5): p. 495–505.25088795
7 Sinclair J, Bentley OS, Abubakar A, Rhodes LA, Marciniak MW. Impact of a pharmacist in improving quality measures that affect payments to physicians. J Am Pharm Assoc (2003). 2019;59(4S):S85–S90. doi: 10.1016/j.japh.2019.03.013. PubMed PMID: 31203017.31203017
8 Wells T, Rockafellow S, Holler M, Coe AB, Yoo A, Choe HM, . Description of pharmacist-led quality improvement huddles in the patient-centered medical home model. J Am Pharm Assoc (2003). 2018;58(6):667–72.e2. doi: 10.1016/j.japh.2018.08.007. PubMed PMID: 30243919.30243919

### No Outcome of Interest (n=7)

1 Chien, A.T., ., Establishing Teams: How Does It Change Practice Configuration, Size, and Composition? Journal of Ambulatory Care Management, 2018. 41(2): p. 146–155.
2 Edwards ST, Rubenstein LV, Meredith LS, Schmidt Hackbarth N, Stockdale SE, Cordasco KM, . Who is responsible for what tasks within primary care: Perceived task allocation among primary care providers and interdisciplinary team members. Healthc (Amst). 2015;3(3):142–9. doi: 10.1016/j.hjdsi.2015.05.002. PubMed PMID: 26384225.26384225
3 Everett, C., ., Physician assistants and nurse practitioners perform effective roles on teams caring for Medicare patients with diabetes. Health Affairs, 2013. 32(11): p. 1942–8.24191084
4 Lukewich, J., ., Team composition and chronic disease management within primary healthcare practices in eastern Ontario: an application of the Measuring Organizational Attributes of Primary Health Care Survey. Primary Health Care Research & Development, 2018. 19(6): p. 622–628.29655397
5 Misra-Hebert, A.D., ., Implementing team-based primary care models: a mixed-methods comparative case study in a large, integrated health care system. Journal of General Internal Medicine, 2018. 33(11): p. 1928–1936.30084018
6 Roblin, D.W., T.M. Vogt, and B. Fireman, Primary health care teams. Opportunities and challenges in evaluation of service delivery innovations. Journal of Ambulatory Care Management, 2003. 26(1): p. 22–35; discussion 36-8.
7 Sinsky, C.A. and T. Bodenheimer, Powering-Up Primary Care Teams: Advanced Team Care With In-Room Support. Annals of Family Medicine, 2019. 17(4): p. 367–371.31285215

### Qualitative Study (n=4)

1 Flinter, M., ., Registered Nurses in Primary Care: Emerging New Roles and Contributions to Team-Based Care in High-Performing Practices. Journal of Ambulatory Care Management, 2017. 40(4): p. 287–296.
2 Hoff, T. and K. Prout, Physician Use of Health Care Teams for Improving Quality in Primary Care. Quality Management in Health Care, 2019. 28(3): p. 121–129.31246774
3 Laing, B.Y., ., Introducing the “teamlet”: initiating a primary care innovation at san francisco general hospital. Permanente Journal, 2008. 12(2): p. 4–9.
4 Roots, A. and M. MacDonald, Outcomes associated with nurse practitioners in collaborative practice with general practitioners in rural settings in Canada: a mixed methods study. Human Resources for Health [Electronic Resource], 2014. 12: p. 69.

### Unavailable (n=4)

1 Miller, J.L., Role of physician extenders on the managed care team. Integrated Healthcare Report, 1994: p. 8–11.
2 Mitchell, J.D., ., Development and Implementation of a Team-Based, Primary Care Delivery Model: Challenges and Opportunities. Mayo Clinic Proceedings, 2019. 94(7): p. 1298–1303.31272572
3 Rauckhorst, L.M., Impact of a physician/nurse practitioner team primary care delivery model on selected geriatric long-term care outcomes. Journal of Nursing Quality Assurance, 1989. 4(1): p. 62–72.2513335
4 Smolowitz, J., ., Role of the registered nurse in primary health care: meeting health care needs in the 21st century. Nursing Outlook, 2015. 63(2): p. 130–6.25261382

### Not Research (n=2)

1 Bauer, L. and T. Bodenheimer, Expanded roles of registered nurses in primary care delivery of the future. Nursing Outlook, 2017. 65(5): p. 624–632.28483137
2 Saxe Zerden L Msw, P., P. Lombardi Bm Msw, and P. Jones A Msw, Social workers in integrated health care: Improving care throughout the life course. Social Work in Health Care, 2019. 58(1): p. 142–149.30569823

### Background (n=1)

1 Wagner, E.H., ., Effective team-based primary care: observations from innovative practices. BMC Family Practice, 2017. 18(1): p. 13.28148227

### Descriptive Study (n=1)

1 Norful, A., ., Utilization of registered nurses in primary care teams: A systematic review. International Journal of Nursing Studies, 2017. 74: p. 15–23.28595110

### Not Primary Care (n=1)

1 Tetuan, C., ., Assessing the Effect of a Telepharmacist’s Recommendations During an Integrated, Interprofessional Telehealth Appointment and Their Alignment with Quality Measures. Journal of Managed Care & Specialty Pharmacy, 2019. 25(12): p. 1334–1339.31778622

### Non-Systematic Review (n=1)

1 Richards A, Carley J, Jenkins-Clarke S, Richards DA. Skill mix between nurses and doctors working in primary care-delegation or allocation: a review of the literature. Int J Nurs Stud. 2000;37(3):185–97. PubMed PMID: 10754184.10754184

### Study Protocol (n=1)

1 Wranik, W.D., ., How best to structure interdisciplinary primary care teams: the study protocol for a systematic review with narrative framework synthesis. Systematic Reviews, 2016. 5(1): p. 170.27716357