# APPENDIX A SEARCH STRATEGIES

## DATABASE SEARCHED & TIME PERIOD COVERED

OVID Medline - From inception to 5/29/2020

## LANGUAGE

English

## SEARCH STRATEGY

((patient care team/ or “patient care team*”.ti,ab OR “team based”.ti,ab OR “team culture”.ti,ab OR “team dynamic”.ti,ab OR “team function*”.ti,ab OR teamwork.ti,ab OR “team work”.ti,ab

OR

“multidisciplinary team*”.ti,ab OR “interdisciplinary team*”.ti,ab OR “integrated care”.ti,ab OR “shared care”.ti,ab) AND ((“primary care” OR “primary health care”).ti,ab or primary care/)

AND

(role.ti,ab OR roles.ti,ab OR responsibilit*.ti,ab OR model.ti,ab OR models.ti,ab OR organization.ti,ab OR organization.ti,ab OR arrangement.ti,ab OR structure.ti,ab OR professional roles/))