# REFERENCES

1 Barry MJ, Edgman-Levitan S. Shared decision making-pinnacle of patient-centered care. N Engl J Med. 2012;366(9):780–1.22375967
2 Crossing the Quality Chasm: A New Health System for the 21st Century. 2001.
3 Menichetti J, Libreri C, Lozza E, Graffigna G. Giving patients a starring role in their own care: a bibliometric analysis of the on-going literature debate. Health Expect. 2016;19(3):516–26.25369557
4 Lines LM, Lepore M, Wiener JM. Patient-centered, Person-centered, and Person-directed Care: They are Not the Same. Med Care. 2015;53(7):561–3.26067878
5 Vick JB, Wolff JL. A scoping review of person and family engagement in the context of multiple chronic conditions. Health Serv Res. 2021;56 Suppl 1(Suppl 1):990–1005.34363217
6 Bernacki RE, Block SD, American College of Physicians High Value Care Task F. Communication about serious illness care goals: a review and synthesis of best practices. JAMA Intern Med. 2014;174(12):1994–2003.25330167
7 Fagerlin A, Zikmund-Fisher BJ, Ubel PA. Helping patients decide: ten steps to better risk communication. J Natl Cancer Inst. 2011;103(19):1436–43.21931068
8 Santana S, Brach C, Harris L, . Updating Health Literacy for Healthy People 2030: Defining Its Importance for a New Decade in Public Health. J Public Health Manag Pract. 2021;27(Suppl 6):S258–S264.33729194
9 Office of Disease Prevention and Health Promotion. Healthy People 2030.
10 Shersher V, Haines TP, Sturgiss L, . Definitions and use of the teach-back method in healthcare consultations with patients: A systematic review and thematic synthesis. Patient Educ Couns. 2021;104(1):118–129.32798080
11 Street RL, Jr., Makoul G, Arora NK, Epstein RM. How does communication heal? Pathways linking clinician-patient communication to health outcomes. Patient Educ Couns. 2009;74(3):295–301.19150199
12 Hong YR, Jo A, Huo J, . Pathways of Teach-Back Communication to Health Outcomes Among Individuals With Diabetes: A Pathway Modeling. J Prim Care Community Health. 2022;13:21501319211066658.34984931
13 Howie-Esquivel J, Bidwell JT. A State-of-the-Art Review of Teach-Back for Patients and Families With Heart Failure: How Far Have We Come? J Cardiovasc Nurs. 2023.
14 Jagodage H, McGuire A, Seib C, Bonner A. Effectiveness of teach-back for chronic kidney disease patient education: A systematic review. J Ren Care. 2024;50(2):92–103.37010245
15 Choi S, Choi J. Effects of the teach-back method among cancer patients: a systematic review of the literature. Support Care Cancer. 2021;29(12):7259–7268.34302545
16 Ha Dinh TT, Bonner A, Clark R, . The effectiveness of the teach-back method on adherence and self-management in health education for people with chronic disease: a systematic review. JBI Database System Rev Implement Rep. 2016;14(1):210–47.
17 Mashhadi SF, Hisam A, Sikander S, . Post Discharge mHealth and Teach-Back Communication Effectiveness on Hospital Readmissions: A Systematic Review. Int J Environ Res Public Health. 2021;18(19).
18 Oh EG, Lee HJ, Yang YL, Kim YM. Effectiveness of Discharge Education With the Teach-Back Method on 30-Day Readmission: A Systematic Review. J Patient Saf. 2021;17(4):305–310.30882616
19 Yen PH, Leasure AR. Use and Effectiveness of the Teach-Back Method in Patient Education and Health Outcomes. Fed Pract. 2019;36(6):284–289.31258322
20 Talevski J, Wong Shee A, Rasmussen B, . Teach-back: A systematic review of implementation and impacts. PLoS One. 2020;15(4):e0231350.32287296
21 EPOC CEPaOoC. What study designs can be considered for inclusion in an EPOC review and waht should they be called? EPOC resources for review authors. . 2017.
22 McGowan J, Sampson M, Salzwedel DM, . PRESS Peer Review of Electronic Search Strategies: 2015 Guideline Statement. J Clin Epidemiol. 2016;75:40–6.27005575
23 Oh EG, Lee JY, Lee HJ, Oh S. Effects of discharge education using teach-back methods in patients with heart failure: A randomized controlled trial. International Journal of Nursing Studies. 2023;140:104453.36827745
24 Proctor E, Silmere H, Raghavan R, . Outcomes for implementation research: conceptual distinctions, measurement challenges, and research agenda. Adm Policy Ment Health. 2011;38(2):65–76.20957426
25 Goni S, Roussety A, Jovanovic M. Assessing adherence and comprehension of cardiovascular medicines with pharmacist intervention post-acute myocardial infarction: a pilot study. Journal of Pharmacy Practice & Research. 2024;54(2):135–144.
26 Mesbahi H, Kermansaravi F, Kiyani F. The Effect of Teach-Back Training on Self-Care and Readmission of Patients with Heart Failure. Medical-Surgical Nursing Journal. 2020;9(3):1–7.
27 Xia J, He J. Impact of dietary management using teach-back method on glucose and lipid metabolism and quality of life in patients with hepatitis B complicated by diabetes. American Journal Of Translational Research. 2021;13(7):8496–8504.34377347
28 Cochrane Collaboration. RoB 2: A revised Cochrane risk-of-bias tool for randomized trials. Available at: https://methods.cochrane.org/bias/resources/rob-2-revised-cochrane-risk-bias-tool-randomized-trials.
29 Daniel Gallardo-Gomez RR, Kerry Dwan. Standardized mean differences in meta-analysis: A tutorial. Cochrane Ev Synth. 2024.
30 Deeks JJ HJ, Altman DG, McKenzie JE, Veroniki AA. Cochrane Handbook for Systematic Reviews of Interventions. Chapter 10: Analysing data and undertaking meta-analysis. 2024
31 Hartung J, Knapp G. On tests of the overall treatment effect in meta-analysis with normally distributed responses. Stat Med. 2001;20(12):1771–82.11406840
32 Hartung J, Knapp G. A refined method for the meta-analysis of controlled clinical trials with binary outcome. Stat Med. 2001;20(24):3875–89.11782040
33 Viechtbauer W. Conducting Meta-Analyses in R with the metafor Package. Journal of Statistical Software. 2010;36(3):1 - 48.
34 PCORI. Strategy Categories. 2025.
35 Burmeister S, Nickasch B. Promoting the Teach-Back Method during hospital admissions. Nursing. 2022;52(7):52–56.
36 Caluya Jr J. Impact of Educational Intervention in Reducing 30-Day Heart Failure Readmission. Medsurg Nursing. 2021;30(5):309–313.
37 Feinberg I, Ogrodnick MM, Hendrick RC, . Perception Versus Reality: The Use of Teach Back by Medical Residents. Health Literacy Research and Practice. 2019;3(2):e117–e126.31294313
38 Holman CK, Weed LD, Kelley SP. Improving Provider Use of the Teach-Back Method. Journal for nurses in professional development. 2019;35(1):52–53.30608325
39 Klingbeil C, Gibson C. The Teach Back Project: A System-wide Evidence Based Practice Implementation. Journal of Pediatric Nursing. 2018;42:81–85.30219303
40 Prochnow JA, Meiers SJ, Scheckel MM. Improving Patient and Caregiver New Medication Education Using an Innovative Teach-back Toolkit. Journal of Nursing Care Quality. 2019;34(2):101–106.30198943
41 Scott C, Andrews D, Bulla S, Loerzel V. Teach-Back Method: Using a Nursing Education Intervention to Improve Discharge Instructions on an Adult Oncology Unit. Clinical Journal of Oncology Nursing. 2019;23(3):288–294.31099800
42 Bei XU, Yang Y, Ping YU. Influence of Teach-back health education model on cognitive behavior and quality of life of elderly patients with high-risk pressure injury. Chinese Evidence-based Nursing. 2023;9(5):931–934.
43 Yinglei XU, Yang M, Yun YE, . Influence of teach-back method combined with multimedia education on foot self-care behavior in patients with high risk diabetic foot. Chinese Evidence-based Nursing. 2021;7(14):1975–1978.
44 张丽娟, 施琴英, 褚志凤, . 回授法健康教育应用于膝关节镜下交叉韧带重建术术后功 能康复锻炼的研究. Nursing of Integrated Traditional Chinese & Western Medicine. 2018;4(10):22–25.
45 李丹阳, 罗旭霞, 黄露芹. Teach-back方法在初发血液肿瘤PICC置管患者健康教育中的应用. Tianjin Journal of Nursing. 2021;29(1):94–97.
46 游晓青, 陈庚, 林文津. 回授法在腰椎间盘突出症患者健康宣教中的应用. Nursing of Integrated Traditional Chinese & Western Medicine. 2018;4(10):129–131.
47 Berthelsen O, Wiklund M, Säthil K, . An evaluation of two different methods for preoperative physical therapy information before abdominal surgery. Journal of communication in healthcare. 2020;13(2):102–110.
48 Cetindemir EO, Cangol E. The effect of breastfeeding education given through the teach-back method on mothers’ breastfeeding self-efficacy and breastfeeding success: a randomized controlled study. BMC Pregnancy and Childbirth. 2024;24(1):453.38951771
49 Ghorbani B, Jackson AC, Noorchenarboo M, . Comparing the Effects of Gamification and Teach-Back Training Methods on Adherence to a Therapeutic Regimen in Patients After Coronary Artery Bypass Graft Surgery: Randomized Clinical Trial. Journal of Medical Internet Research. 2021;23(12):e22557.34890346
50 Griffey RT, Shin N, Jones S, . The impact of teach-back on comprehension of discharge instructions and satisfaction among emergency patients with limited health literacy: A randomized, controlled study. J Commun Healthc. 2015;8(1):10–21.26617669
51 Joseph D, Hu R, Min R, . Use and Utility of Patient After-Visit Instructions at a University Rheumatology Outpatient Clinic: Status and Randomized Prospective Pilot Intervention Study. ACR Open Rheumatology. 2024;6(5):321–329.38387613
52 Nas MA, Cayir Y, Bilen A. The impact of teach-back educational method on diabetes knowledge level and clinical parameters in type 2 diabetes patients undergoing insulin therapy. International Journal of Clinical Practice. 2021;75(4):e13921.33336836
53 Press VG, Arora VM, Kelly CA, . Effectiveness of Virtual vs In-Person Inhaler Education for Hospitalized Patients With Obstructive Lung Disease: A Randomized Clinical Trial. JAMA Network Open. 2020;3(1):e1918205.31899529
54 Rahmani A, Vahedian-Azimi A, Sirati-Nir M, . The Effect of the Teach-Back Method on Knowledge, Performance, Readmission, and Quality of Life in Heart Failure Patients. Cardiology Research and Practice. 2020;2020:88978811.
55 Saadatian M, Yoosefian N, Saravi FK, Yaghoubinia F. The Effect of the Teach-Back Method on Illness Perception and Self-efficacy in Patients with Coronary Artery Disease. Medical-Surgical Nursing Journal. 2022;11(1):1–9.
56 Satehi SB, Zandi M, Derakhshan HB, . Investigating and Comparing the Effect of Teach-Back and Multimedia Teaching Methods on Self-Care in Patients With Diabetic Foot Ulcers. Cd (Clinical Diabetes). 2021;39(2):146–152.
57 Shen D, Huang W, Wei S, . The impact of Teach-back method on preoperative anxiety and surgical cooperation in elderly patients undergoing outpatient ophthalmology surgery: A randomized clinical trial. Medicine. 2023;102(8):e32931.36827029
58 Teshnizi SH, Sadeghpour S, Faghih A. The Effectiveness of an Educational Intervention Based on Teach-back Method with Adherence to Treatment in Patients with Type 2 Diabetes. Journal of Health Sciences & Surveillance System. 2024;12(1):12–19.
59 Tran S, Bennett G, Richmond J, . ‘Teach-back’ is a simple communication tool that improves disease knowledge in people with chronic hepatitis B - a pilot randomized controlled study. BMC Public Health. 2019;19(1):1355.31647001
60 Proctor EK, Bunger AC, Lengnick-Hall R, . Ten years of implementation outcomes research: a scoping review. Implement Sci. 2023;18(1):31.37491242
61 IHA. Teach-back Conviction, Consistency, and Confidence Self-assessment. .
62 Hanham J, Castro-Alonso JC, Chen O. Integrating cognitive load theory with other theories, within and beyond educational psychology. Br J Educ Psychol. 2023;93 Suppl 2:239–250.37208145
63 Pusic MV, Ching K, Yin HS, Kessler D. Seven practical principles for improving patient education: Evidence-based ideas from cognition science. Paediatr Child Health. 2014;19(3):119–22.24665218
64 Manojlovich M, Hofer TP, Krein SL. Advancing Patient Safety Through the Clinical Application of a Framework Focused on Communication. J Patient Saf. 2021;17(8):e732–e737.30383622
65 Kreps G OHD, Clowers M. . The Influences of Human Communication on Health Outcomes. American Behavioral Scientist. 1994;38:248–256. .
66 Improvement IfH. Always Use Teach-Back!
67 Powell BJ, Beidas RS, Lewis CC, . Methods to Improve the Selection and Tailoring of Implementation Strategies. J Behav Health Serv Res. 2017;44(2):177–194.26289563
68 Smith NR, Knocke KE, Hassmiller Lich K. Using decision analysis to support implementation planning in research and practice. Implement Sci Commun. 2022;3(1):83.35907894
69 Fernandez ME, Ten Hoor GA, van Lieshout S, . Implementation Mapping: Using Intervention Mapping to Develop Implementation Strategies. Front Public Health. 2019;7:158.31275915
70 AHRQ. Guide to Improving Patient Safety in Primary Care Settings by Engaging Patients and Families. Content last reviewed February 2023. Agency for Healthcare Research and Quality, Rockville, MD.; 2023.
71 C B. AHRQ Health Health Literacy Universal Precautions Toolkit, 3rd Edition. Rockville, MD. Agency for Healthcare Research and Quality. AHRQ Publication No. 23-0075.; 2024.
72 Affairs UDoV. Veterans Health Administration. 2025.
73 Brach C KD, Hernandez LM, Baur C, Parker R, Dreyer B, Schyve P, Lemerise AJ, Schillinger D. Ten Attributes of Health Literate Health Care Organizations. Institute of Medicine of the National Academies. 2012.
74 Skidmore ER. Training to Optimize Learning after Traumatic Brain Injury. Curr Phys Med Rehabil Rep. 2015;3(2):99–105.26217546
75 Landes SJ, McBain SA, Curran GM. An introduction to effectiveness-implementation hybrid designs. Psychiatry Res. 2019;280:112513.31434011
76 SHEP Questionnaires. Vol. 2025. VHA Office of Quality and Patient Safety Performance Measurement.