# ACKNOWLEDGMENTS

The authors are grateful to Rebecca L. Watkin, PhD (CHB Wordsmith, Inc) and Liz Wing for editorial and citation management support, and the following individuals for their contributions to this project:

## Operational Partners

Operational partners are system-level stakeholders who help ensure relevance of the review topic to the VA, contribute to the development and approval of the final project scope and timeframe for completion, provide feedback on the draft report, and provide consultation on strategies for dissemination of the report to the field and relevant groups.

- Michael Goldstein, MD
  Associate Chief Consultant for Preventive Medicine
  VHA National Center for Health Promotion and Disease Prevention, Office of Patient Care Services

- Daniel Greenwood, PhD, RD
  National Program Manager, Patient Centered Learning
  VHA National Center for Health Promotion and Disease Prevention, Office of Patient Care Services

- Angela Sankarkumar, MPH
  National Program Manager, Veterans Health Education and Information
  VHA National Center for Health Promotion and Disease Prevention, Office of Patient Care Services

## Technical Expert Panel

To ensure robust, scientifically relevant work, the technical expert panel (TEP) guides topic refinement, provides input on key questions and eligibility criteria, advising on substantive issues or possibly overlooked areas of research, assures VA relevance, and provides feedback on work in progress. TEP members included:

- Maya Gerstein, DrPH
  Health Scientist Administrator
  Agency for Healthcare Research and Quality

- Scott Pawlikowski, MD
  Director of Improvement and Innovation
  VA Office of Primary Care

- Marla Clayman, PhD, MPH
  Research Health Scientist
  Center for Healthcare Organization and Implementation Research (CHOIR)
  VA Bedford Healthcare System

- Howard Gordon, MD
  Staff Physician
  Jesse Brown VA Medical Center (JBVAMC)
  Chair
  Institutional Review Board, JBVAMC
  Associate Director
  Center of Innovation for Complex Chronic Healthcare, JBVAMC

- Kathryn Pollak, PhD
  Professor
  Population Health Sciences, Department of Family Medicine and Community Health
  Duke University School of Medicine