# DISCUSSION

We found that the use of teach-back for patient education improves short-term (3 months or less), self-reported patient adherence to clinically important health behaviors, and efficacy for self-management of health conditions. While we found no clear benefit of teach-back on short-term knowledge acquisition, serious methodologic limitations identified in these studies limited our certainty of this finding. There was no evidence that the effect of teach-back varied between inpatient and outpatient settings and we found no studies that evaluated differences in the effect of teach-back by delivery mode (eg, in-person versus virtual), type of professional delivering the education, or patient-level characteristics (eg, low versus high health literacy). Methods for clinical implementation of teach-back have not been well studied, though staff training, supporting clinician practice change (eg, using clinical reminders), and preparing clinical sites for implementation (eg, assessing unit readiness for teach-back) appear to be common strategies. Limited uncontrolled, observational evidence suggests that clinician adoption of, and fidelity to, teach-back increased after a variety of implementation approaches.

Our review builds on prior evidence syntheses by focusing on evidence drawn from RCTs of teach-back across a variety of inpatient and outpatient settings. While our findings generally support prior reviews on the benefits of teach-back with respect to adherence and self-efficacy, unlike prior reviews we did not find clear evidence for effect on patient knowledge acquisition. We suspect this may be due to several contributing reasons. First, approaches to measuring knowledge were inconsistent, unvalidated, and often lacked an explicit link to intervention content. Measures ranged from patient perceptions of information comprehension to knowledge checks, to skill demonstration (in a single study). Second, no studies evaluated the effect of teach-back on a simple, single piece of information. All interventions included multiple educational objectives (eg, topics or action steps)—even those that addressed what the authors categorized as single behavior. For example, 1 intervention focused on “correct inhaler use,” which includes 12 different steps, even though it is described as a single behavior. In another example, an intervention focused on “post-operative physical activity” included 3 different subcategories of early mobilization/ambulation techniques, breathing exercises, and information about physical activity and restrictions after discharge.^47^ Third, it is likely that teach-back is not sufficient to solely improve patient knowledge in certain settings and may need to be combined with other educational strategies. Examples of settings requiring this approach would include when a patient is experiencing a high cognitive load while transitioning to a new norm (eg, new diagnosis) or a heightened state of distress (eg, hospital discharge). Adult learning and education literature suggest that allowing the patient to set the pace of information flow, chunking complex information into smaller conceptual sections (ie, chunks) to aid comprehension and recall, using visual aids, and patient demonstration is recommended in such circumstances.^62,63^

As noted above, our confidence regarding the finding about the effectiveness of teach-back on knowledge is low. However, it is possible that teach-back does not promote improved knowledge, but does promote improved affective (eg, self-efficacy) and behavioral (eg, adherence) outcomes. This is consistent with theoretical work that explains that communication around health information is far more complex than a simple exchange of simple information^64^ and effective communication may not act via cognitive processes such as knowledge acquisition.^65^

Despite the limitations of our findings and the measurement approaches used in the identified literature, the potential benefit of this low-risk intervention on adherence and self-efficacy compared to usual approaches to patient education may support its continued use in clinical practice. In particular, we found that a small number of patients would need to receive teach-back for 1 patient to experience a benefit on adherence or self-efficacy. To realize the benefits of teach-back, high fidelity practice will be needed (ie, intervention was delivered as intended related to dose, content, form) by a majority of clinicians, at most patient learning opportunities.

Teach-back has already been identified and adopted as a preferred strategy for promoting and advancing patient education by large health care systems and advocacy organizations such as the VHA,^10^ AHRQ, and the Institute for Healthcare Improvement.^66^ Unfortunately, we were unable to draw conclusions about successful teach-back implementation methods in routine care. We found no studies comparing effectiveness of implementation strategies (eg, audit and feedback versus identifying and preparing clinical champions) for teach-back in health care settings, and very few objectively assessing any implementation-focused outcomes (eg, adoption, fidelity). In lieu of clear evidence on optimal implementation strategies to promote the use of teach-back specifically, health systems can look to existing guidance on how implementation strategies should be selected for a given setting and intervention,^67–69^ including the AHRQ Health Literacy Universal Precautions toolkit^70,71^.

## Clinical Context

The VHA provides care to over 9 million Veterans across 1,380 health care facilities.^72^ Each health care encounter with a Veteran is an opportunity to provide patient education in pursuit of promoting understanding of care received, encourage self-management of chronic conditions, and support shared decision-making. The specific education strategy chosen for each patient encounter must be matched to the clinical context, the knowledge conveyed, the clinician’s skillset, and patient readiness, motivation, and learning style. The VHA’s Patient Centered Learning Program will advocate for implementing and evaluating teach-back initiatives in VHA clinical settings as a key strategy for advancing VHA’s efforts to become a health-literate health care organization.^73^ Teach-back is a low-risk strategy that can be adapted to any setting and delivered by any clinician with the primary cost being time. However, the implementation of teach-back in VHA requires a multifaceted approach to train clinicians (both initially and for maintenance), to develop resources and processes to encourage and support use of this practice, and ways to ensure this happens with the right encounters and the right patients at the right time. Currently, we do not know in which clinical contexts teach-back works best. It is possible that such a low-touch educational approach would be best suited to when the knowledge or skills conveyed are relatively focused (eg, inhaler use, medication taking instructions) and may need to be combined with other patient education strategies to support patient learning preferences. As a learning health care system, the VHA is well situated to evaluate and identify implementation strategies for teach-back in clinical contexts.

## Limitations

As with any systematic review, our assessment of the effectiveness of teach-back was limited by the quality and rigor of the relevant published literature. Limitations included the small size of individual studies (most had < 100 participants), a couple^26,55^ of which were self-described as quasi-experimental and 9^25,26,50,51,53–56,58^ which had at least some concerns about ROB in their randomization process. Few provided detailed descriptions of comparator arms, and we found variations in how outcomes were conceptualized, measured (eg, not using validated measures, mostly self-report), and reported (eg, without including variance) which substantially influenced the validity of results. In addition, the identified literature did not include studies limited to populations with relevant patient-level characteristics (eg, literacy level, health status, age) nor studies reporting outcomes stratified by these variables which would be required to draw meaningful statistical conclusions about the impact of an intervention by patient characteristics. None of the identified studies were conducted in the VHA, which may limit the applicability of our findings to the VHA population.

Design choices in our methodology also should be considered for their potential impact on our findings. As we did not limit our literature search to English language-only articles, we identified many potentially eligible abstracts and full text articles in non-English languages for which we were unable to obtain a reliable translation. It is possible that some of this literature could contain relevant findings that were not captured. As we did not identify any studies that used standard language to describe implementation strategies used to encourage clinical groups to use teach-back, we assigned strategies to activities described in available publications. As many descriptions were brief, it is possible that our categorization did not fully reflect the strategies as they took place. Finally, our prioritization of RCTs for abstraction and analysis for KQ1 meant that we did not incorporate findings from 7 non-randomized comparison studies and historically controlled cohort studies. However, the findings from these studies were generally consistent with those of RCTs, with the exception that the uncontrolled studies showed greater benefit of teach-back on knowledge (observational studies often report larger effect estimates than controlled trials).

## FUTURE RESEARCH

While teach-back has already been endorsed in clinical practice, there are still important unanswered questions. First, we need to understand for which patients teach-back is most effective and impactful. The existing literature is primarily focused on general patient populations without attention to those with specific learning or communications needs. For example, in the VHA many Veterans have a history of traumatic brain injuries which can impact their concentration and/or ability to intake new health information.^74^ Only 1 study evaluated the effect of teach-back in a population with a suspected increased risk of low health literacy or a potentially higher risk for misunderstanding. Specifically, Griffey et al recruited patients with low health literacy to receive teach-back to improve comprehension of ER discharge instructions.^50^ As noted, no studies reported results stratified by health literacy status, which prevented our ability to draw conclusions about effectiveness in this critical population compared with a general pool of patients seeking care. Future work targeting patients most vulnerable to barriers to acquiring critical health information would be valuable. Unfortunately, no studies explicitly sought the inclusion of caregivers in the receipt of teach-back. The VHA is strongly committed to Veteran Care Partner engagement and involving them in the deployment of teach-back approaches may enhance outcomes and could be a focus for future evaluation.

Second, we need to know in which settings and for which conditions and health behaviors teach-back is most effective and impactful. Most of the identified literature used teach-back to convey relatively complex health content covering multiple behaviors and information topics (eg, self-care for heart failure). It is possible this education technique is best suited to providing education on a single topic compared to complex information. Evaluating teach-back in a variety of clinical settings will be helpful to guide implementation. While the NNT for teach-back is low for key outcomes, the primary cost is time and staff effort which could otherwise be dedicated to other educational approaches. Future studies should also collect data on potential downsides to the use of teach-back, including unintended consequences of its implementation.

Third, we need to determine how to encourage clinical staff to correctly and reliably use teach-back over time. Monitoring and reporting on the fidelity of teach-back is key to contextualizing null findings and supporting accurate conclusions about positive studies. Only 1 of the trials addressing KQ1 reported monitoring fidelity of teach-back delivery.^51^ Behavior changes among health care providers, as well as for patients, can be challenging and often require reinforcement over time to promote maintenance and accuracy. In addition, studies comparing the effectiveness of implementation strategies for teach-back in health care settings that use accepted taxonomies of implementation strategies and outcomes would provide needed information to guide future promotion of teach-back. Given residual questions about effectiveness of teach-back on key outcomes such as knowledge acquisition, hybrid effectiveness-implementation study designs would be appropriate.^75^

Finally, all future studies on the impact and implementation of teach-back would benefit from rigorous controlled study designs that objectively assess knowledge and skill acquisition using validated and standardized approaches to outcome measurement. This is in keeping with recent recommendations for implementation studies to use consistent terminology. Recommendations for future research on teach-back are provided in Table 3.^60^

Table 3 Recommendations for Future Research on Teach-Back

Domain | Study Design Targets for Future Research
Population | - Individuals who may experience or benefit from teach-back differently, including those with low health literacy, traumatic brain injury, dementia, and/or other learning needs; - Individuals with newly diagnosed chronic diseases (eg, hypertension); - Individuals for whom English is a second language or not preferred; - Care partners
Intervention | - Standardized and well described teach-back interventions; - Teach-back for use in complex settings such as primary care in which multiple disease processes are addressed simultaneously; - Teach-back for use in mental health settings; - Teach-back for use in self-management and rehabilitation programs; - Well-defined implementation strategies identified by established categorizations such as ERIC (Expert recommendations for implementing change)^67^
Comparator | - Clear descriptions of comparator arms; - Patient education approaches with and without teach-back
Outcomes | - Validated measures of proximal (eg, knowledge), intermediate (eg, health behaviors, measures of self-care, medication adherence) and long-term (eg, disease outcomes, utilization) health outcome; - Additional aspects of patient experience such as those included in the VHA Survey of Healthcare Experiences of Patients^76^; - Validated and consistent outcome terminology for implementation outcomes
Timing | - Long-term outcomes (sustained behavior change, chronic condition outcomes, utilization of health care services)

## CONCLUSIONS

Teach-back can be a straightforward and low-risk health education strategy that improves patient self-efficacy and adherence to recommended health behaviors, including self-care. Areas of residual uncertainty include impact on health knowledge and skill acquisition, patient experience with teach-back, and how to successfully implement routine use of teach-back. Additional important questions remain about the duration of effect and for which populations and clinical contexts teach-back would be most useful. Studies of the real-world impact of teach-back that also evaluate which strategies are most effective at increasing the routine use of teach-back are needed. Such findings could improve the incorporation of this communication approach across clinical settings and ultimately impact meaningful patient and population outcomes.