# RESULTS

## LITERATURE FLOW DIAGRAM

The literature flow diagram summarizes the results of the study selection process. A full list studies excluded at the full-text level is provided in the Appendix.

Literature flow diagram summarizing results of study selection process.

## OVERVIEW OF INCLUDED STUDIES

Our search yielded 2,671 unique records, of which 36 met eligibility criteria. Among the eligible studies, 29 evaluated the effectiveness of teach-back interventions (KQ1) and 7^35–41^ described approaches to the implementation of teach-back interventions (KQ2). Of the 29 studies evaluating effectiveness, 5^42–46^ were published in languages other than English and we were unable to acquire translations adequate for design verification, eligibility, or data abstraction. Sixteen^23,25,26,47–59^ of the remaining 24 KQ1 studies were identified as randomized controlled trials (RCTs) and prioritized for data abstraction and synthesis. Of studies describing implementation of teach-back interventions, all 7^35–41^ were single site, pre-post studies. Studies included for KQ1 and KQ2 were conducted in the United States, Sweden, Turkey, Iran, Australia, China, and Korea. We identified no studies among VHA patients or conducted by VHA.

## KQ1A WHAT IS THE EFFECT OF TEACH-BACK ON PATIENT AND PROVIDER OUTCOMES?

A total of 1,737 study participants were analyzed across all KQ1 studies. Of the 16 RCTs analyzed for KQ1, 9^25,47,48,50–52,57–59^ were conducted in outpatient settings and 7^23,26,49,53–56^ were conducted in inpatient settings. Teach-back was compared to usual care in 15 of the 16 included studies.^23,25,26,47–52,54–59^ One study^53^ compared in-person teach-back to virtual asynchronous self-assessment questions. Studies conducted in outpatient settings focused on a variety of health conditions including breastfeeding,^48^ myocardial infarction,^25^ abdominal surgery,^47^ rheumatologic diseases,^51^ diabetes,^52,58^ ophthalmic surgery,^57^ and chronic hepatitis B,^59^ and conditions evaluated in an ED.^50^ In the inpatient setting, studies focused on post-operative self-management after coronary artery bypass graft (CABG) surgery,^49^ heart failure,^23,26^ obstructive lung disease,^53^ coronary artery disease,^55^ and diabetes.^56^ Only 9^23,26,48,52,54–58^ of the included studies reported data on participant age, of which 8 had an average participant age of over 50, while the study on breastfeeding^48^ had an average participant age of 26. One study^50^ examined the use of teach-back among patients with limited health literacy. See Appendix for further study characteristic information.

### Intervention Characteristics

The majority of studies used teach-back during a face-to-face interaction.^23,26,47–50,52–59^ Teach-back interventions were administered by a variety of professionals, most commonly identified as research staff without further detail provided.^26,48,49,53,55,56,58,59^ Six studies combined additional educational strategies with teach-back including written instructions,^51,57,58^ individualized information,^25^ and the use of educational materials developed for people with low literacy.^48,59^ The time spent on teach-back interventions was not universally reported. Among 7 studies that included this information, time spent ranged from 2 to 15 minutes^51,53,59^ to longer time periods of 45 to 135 minutes,^49,52,55^ with a median of about 47 minutes. Our eligibility criteria dictated that included studies had to focus on teach-back from a single encounter, defined as an individual outpatient visit or a single hospital admission. Two studies that occurred in the inpatient setting ^26,55^ included multiple scheduled sessions with teach-back within a single hospital admission. Only 1 study^53^ did not specifically identify their intervention as teach-back, but instead labeled it “teach-to-goal” with the target being correct demonstration of inhaler use.

While all but 1 study used the term “teach-back” to describe the patient education intervention studied, there was varying levels of detail explaining the steps involved in each study’s approach.^10^ In 13 studies,^23,26,47,48,50–52,54–59^ it was clearly documented that the individual delivering teach-back requested that participants describe what they learned using their own words. Three studies^26,57,59^ included what has been called a “teach-back initiation phrase”^10^ that frames a request for teach-back as an assessment of the clarity of the speaker’s communication rather than quizzing the recipient of the communication (eg, including a phrase like “can you tell me back what I said so I know that I explained the material clearly”). Additional rounds of teaching were offered as needed in 9 studies.^23,48,52,53,55–59^ A single KQ1 study^51^ and 4 KQ2 studies assessed fidelity to the teach-back process.^37,38,40,41^ No included studies described a separate teach-back intervention for caregivers.

### Outcomes Overview

We identified all KQ1 outcomes reported in the included studies and categorized them as proximal (eg, knowledge, satisfaction), intermediate (eg, adherence, self-efficacy), or distal (eg, health care utilization, blood pressure) informed by the approach described by Street et al.^11^ (See Appendix for analytic framework and Appendix outcomes list.) Of the 16 included RCTs, 13 articles reported a mix of proximal, intermediate, and distal outcomes. Eight^25,47,50–53,57,59^ included proximal outcomes^25,47,50–53,57,59^ and 2^50,51^ included more than 1 proximal outcome. The main proximal and intermediate outcomes are described above in detail. Nine articles^23,25,26,47,51–54,57^ included distal outcomes, including a mixture of health care visits, signs and symptoms related to disease control, and hospital readmissions.

### Knowledge Acquisition

#### Summary of Findings

Across 8 RCTs that evaluated the effect of teach-back on patient knowledge, we found no clear pattern of effect from teach-back on short-term patient knowledge acquisition (Figure 1). For this analysis, we included outcomes that measured a patient’s incorporation of new information or skills as conveyed by the teach-back intervention. Approaches to assessing knowledge change after teach-back interventions varied both conceptually and in application, and most used author-developed tools for outcome measurement. This conceptual inconsistency precluded calculation of a summary effect size; we therefore synthesized findings narratively. Three studies^47,52,53^ had low ROB, 2^57,59^ had some ROB concerns, and 3^25,50,51^ had high ROB. Sources of bias across these studies included concerns about randomization, unreported follow-up rates or high loss to follow-up, and un-concealed outcome assessment.

Figure 1 Effect of Teach-Back versus Usual Care on Knowledge Acquisition

Notes. For 4 studies, multiple knowledge-related outcomes were reported without an overall summary measure and thus a single study may be represented in more than 1 row of this figure.^50–53^ See Methods for multilevel analysis approach. One study compared teach-back to virtual asynchronous assessment questions instead of usual care.^53^

Abbreviations. CVD=cardiovascular disease; ER=emergency room: SMD=standardized mean difference.

Forest plot of the effect of teach-back on knowledge acquisition across 8 included studies reporting this outcome. No summary effect estimate is shown given the variability in knowledge acquisition assessment. Individual standardized mean differences range from -0.98 to 1.76 and 95% CIs range from -3.53 to 2.35.

#### Detailed Findings

One^53^ RCT took place in the inpatient setting, with 7^25,47,50–52,57,59^ taking place in outpatient settings (1^50^ of which took place in the ED). The number of patients randomized in each trial ranged from 31 to 408. Disease contexts included obstructive lung disease,^53^ myocardial infarction,^25^ abdominal surgery,^47^ rheumatologic diseases,^51^ diabetes,^52^ ophthalmologic conditions requiring surgery,^57^ chronic hepatitis B,^59^ and conditions evaluated in an adult ED.^50^ All but 1 study included a comparison of teach-back to usual care; 1 study^53^ compared teach-back to virtual asynchronous assessment questions instead of usual care. Three studies^25,50,51^ had high ROB, 2 studies^57,59^ had some ROB concerns, and 3 studies^47,52,53^ had low ROB. Common causes of ROB among trials reporting patient knowledge after teach-back included missing outcome data and outcome measurement methods.

For all but 1^59^ of the studies that assessed a knowledge outcome, knowledge was the primary outcome assessed. Knowledge assessments occurred immediately after the educational component delivery,^50,52,53,59^ days to weeks after intervention delivery,^25,47^ or a month or more later.^25,52,53,59^ In 1 study,^57^ the timing of knowledge assessment was not specified. Knowledge was assessed in 2 primary ways. The first was to assess a participant’s own perception of their knowledge or understanding of relevant health topics (ie, perceived comprehension), which was used by 2 studies.^50,57^ The second approach was to evaluate skill demonstration or direct assess the participant’s knowledge via fact-based questions (ie, knowledge check), which was used in 7 studies.^25,47,50–53,59^ One study^50^ included both perceived comprehension and knowledge check assessments. Only 1 study^53^ assessed skill demonstration and correct inhaler technique among hospitalized patients with obstructive lung disease.

Five studies^25,47,50,51,57^ used measures of knowledge that were developed by study authors and had not been previously used or validated. One study^52^ acknowledged that there were no validated measures of the outcome (diabetes knowledge level [DKL]) available in the appropriate language (Turkish) and thus created their own tool. Two studies^53,59^ based their knowledge outcome on prior research or modification of a knowledge outcome measure that was previously validated.

Two of the 8 RCTs found that the teach-back intervention significantly improved knowledge. Five RCTs^25,47,50,51,57^ found no significant differences in knowledge after a teach-back intervention compared to usual care. One RCT^53^ was a comparative effectiveness study that found that a virtual educational intervention (which the authors called an “in-person teach-to-goal” intervention) had a similar effect to teach-back in a non-inferiority analysis. No studies favored a usual care comparator.

One low-ROB study^52^ favored the teach-back intervention among patients with type 2 diabetes. In this study, participants in the teach-back group had a significantly higher score (mean [SD]) on an investigator-developed Turkish DKL instrument (range = 0–22) after the teach-back intervention (before: 10.2 [2.1], after: 16.9 [2.1]) compared to the usual care group (before: 11.2 [2.3], after: 14.1 [2.0]) (p < .05). Intervention group participants continued to have higher scores on the DKL at 3 months compared to usual care participants. A second low-ROB study of participants undergoing major abdominal surgery did not find significant differences between the intervention group and control group in the number of correct statements (out of a total of 29) regarding (1) early mobilization/ambulation; (2) breathing exercises; and (3) physical activity and restrictions. Intervention group participants averaged 30.0% correct answers, and the usual care group averaged 25.4% correct responses (p = 0.18). Notably, the study was not powered on finding meaningful differences between groups on this measure. Lack of power may therefore explain the study’s null findings. The third low-ROB study^53^ that assessed knowledge outcomes was a comparative effectiveness study of a virtual teach-to-goal intervention for correct inhaler use and an in-person teach-to-goal intervention among hospitalized patients with obstructive lung disease. We considered the virtual (video-based) arm to be the comparator (as it did not ask participants to repeat or demonstrate what was taught) and the in-person arm to be the teach-back intervention (as it met the classifying criteria). The proportion of participants who had correct inhaler technique in the comparator arm and the teach-back arm were similar (67% versus 66%), but the comparator arm did not meet the a priori non-inferiority significance level.

### Adherence

#### Summary of Findings

Seven studies assessed the effect of teach-back on adherence, based on the demonstration or reporting of practicing the health behavior(s) instructed during the intervention. We performed a meta-analysis on 6 of these studies,^23,25,26,48,49,58^ excluding 1^57^ due to inconsistency in outcome reporting. In the meta-analysis, we found that teach-back had a beneficial effect on adherence to relevant health behaviors compared to usual care when measured 3 months or less from the end of the intervention. The meta-analysis encompassed data from 497 patients and showed that teach-back led to a moderate increase in adherence (SMD = 0.68, 95% CI [0.53, 0.84]) (Figure 2). To further contextualize this finding using the NNT, we found that approximately 3 patients would need to receive teach-back (NNT = 2.69) for 1 patient to experience improved adherence. Moderate heterogeneity was apparent in these findings (95% PI [0.44, 0.93]), suggesting that the benefits of teach-back on adherence could vary from small to large in magnitude (ranging from approximately 2.05 to 4.10 patients needing to receive teach-back for 1 patient to experience improved adherence). There were no low-ROB studies, 5^23,26,48,49,58^ with some ROB concerns,^57^ and 1^25^ with a high ROB. Common causes of ROB included concerns about randomization, deviations from intended interventions, outcome measurement issues, and selection of reported results.

Figure 2 Meta-Analysis of the Effect of Teach-Back versus Usual Care on Adherence

Notes. Multiple outcomes are reported in the meta-analysis originating from 1 study.^49^ See Methods for details on relevant adjustment.

Abbreviations. CABG=coronary artery bypass graft; SMD=standardized mean difference.

Forest plot of the effect of teach-back on adherence outcomes across 6 studies. Although two individual study 95% CI overlap 0, teach-back interventions increase adherence compared to usual care. The summary SMD is 0.68 (95% CI 0.53 to 0.84) and a 95% prediction interval of 0.44 to 0.93.

#### Detailed Findings

Overall, 7 RCTs^23,25,26,48,49,57,58^ assessed the effect of teach-back interventions on adherence, which was the primary outcome in 5.^23,25,26,49,58^ Four^23,26,48,49^ took place in the inpatient setting and 3 ^25,57,58^ in the outpatient setting. None measured adherence more than 3 months after the teach-back intervention. The number of randomized patients ranged from 31 to 123. Disease contexts included breastfeeding,^48^ post CABG care,^49^ heart failure,^23,26^ myocardial infarction,^25^ type 2 diabetes,^58^ and outpatient ophthalmology surgery.^57^ All studies compared teach-back to usual care. Adherence was assessed at a range of time points including immediately after the intervention, 1-day post-intervention, and up to 3 months post-intervention. Adherence was assessed differently in each of the 7 studies, using the following 7 instruments: (1) the LATCH (latch, audible swallowing, type of nipple, comfort and hold) scale for breastfeeding^48^; (2) a validated questionnaire for diet and physical activity regimens^49^; (3) Morisky Medication Adherence Score for medication adherence^25,49^; (4) the European Heart Failure Self Care Behavior Scale^26^; (5) degree of surgical cooperation^57^; (6) the self-care of Heart Failure Index^23^; and (7) the Modanloo treatment adherence questionnaire for medication adherence.^58^ Among these assessment tools, all but the LATCH scale and degree of surgical cooperation used self-reported adherence rather than observation. One example of a study that used observation to measure adherence compared the use of teach-back for pre-operative education on perioperative “cooperation” (eg, head and eye positioning during surgery) to standard education methods in a group of 116 elderly adults undergoing ophthalmologic surgery.^57^ Patients were rated on a 3-point scale (good, general, poor) based on their intraoperative cooperation with more patients in the intervention group demonstrating good cooperation compared with those in the control group (33 versus 22, p = 0.038).

Notably, in the 2 studies that evaluated adherence to medication use,^25,49^ no statistically significant differences were found between the teach-back and control groups.

### Self-Efficacy

#### Summary of Findings

Five RCTs assessed the effect of teach-back on self-efficacy or the belief in one’s capacity to successfully perform a relevant health behavior. We found that teach-back had a beneficial impact on self-efficacy for health behavior based on a meta-analysis including 342 patients from the 4 studies reporting a validated self-efficacy measure (Figure 3). Specifically, teach-back led to a large increase in self-efficacy relative to usual care (SMD = 1.26, 95% CI [0.75, 1.77]). This SMD translates to a NNT of 2 patients needing to receive teach-back for 1 patient to experience improved self-efficacy related to a specific health care behavior. This estimate is associated with substantial heterogeneity (95% PI [0.22, 2.30]) ranging from no benefit to a large benefit of teach-back on self-efficacy (NNT ranging from 1 to 8). Potential sources of heterogeneity among these studies included the length of follow-up, population characteristics (eg, health condition, age), and varying measures of self-efficacy. The studies included in the meta-analysis also differed in ROB, with 3 studies^23,48,56^ reporting some concerns across varying domains and 1^55^ reporting a high level of concern largely due to imbalance of key baseline variables and limited description of randomization procedures. One study^54^ was not included in the meta-analysis due to lack of clarity in the reporting of this outcome.

Figure 3 Meta-Analysis of the Effect of Teach-Back versus Usual Care on Self-Efficacy

Notes. Thirty participants in Satehi et al were not included in the meta-analysis as they were in an ineligible arm.

Abbreviations. SMD=standardized mean difference.

Forest plot of 4 studies reporting the effect of teach-back on self-efficacy outcomes. All individual study standardized mean differences favor the teach-back intervention over usual care. The summary standardized mean difference is 1.26 (95% CI 0.75 to 1.77) and the 95% prediction interval ranges from 0.22 to 2.30.

#### Detailed Findings

Overall, 5 studies evaluated the effects of teach-back on self-efficacy across breastfeeding,^48^ self-care behaviors for heart failure,^23^ cardiovascular disease,^54,55^ and diabetes management.^56^ All studies were conducted in inpatient settings, with a total of 412 participants (although 1 study^55^ [N = 100] only reported the randomized sample and not the number analyzed). The majority of studies included samples with a mean age over 50 years, although a study investigating the effect of teach-back on breastfeeding self-efficacy in a sample of postpartum women reported a mean age of 26.23 years (SD = 4.77).

Of note, all studies comparing teach-back to usual care reported statistically significant improvements in self-efficacy while the 1 study^56^ with an active control comparator condition consisting of multimedia education with no teach-back reported no difference in post-intervention self-efficacy. This study compared the receipt of a single, 45-minute in-person education session using teach-back to the receipt of the same information via 45-minute education videos (via CD, DVD, and mobile device files) and to patient education via usual approach among 90 patients with diabetic foot ulcers. Both studies that measured both self-efficacy and adherence^23,48^ found beneficial effects on each outcome.

### Patient Satisfaction

#### Summary of Findings

We found insufficient evidence on the effect of teach-back on patient satisfaction to draw meaningful conclusions.^50,51^ Two United States-based RCTs with high ROB reported patient satisfaction after clinical encounters using teach-back compared to usual care. Reasons for ROB included unclear allocation concealment, poorly described randomization, baseline imbalances between arms, inadequate consideration of cross-over, high rates of loss to follow-up or missing detail on dropout rates, and unblinded outcomes assessment.

#### Detailed Findings

One study evaluated satisfaction using 4 items derived from the Agency for Healthcare Research and Quality (AHRQ)’s validated Consumer Assessment of Healthcare Providers and Systems (CAHPS) questionnaire among 254 patients with low health literacy in an urban academic ED, who were randomized to receive either standard discharge instructions or instructions delivered using teach-back. There was no statistically significant difference in satisfaction between arms related to time in the ED, discharge instructions, whether the team explained things in an easy-to-understand way, and if they would recommend the ED to a friend.^50^ However, the 95% CI for the odds of satisfaction with the ease of understanding (odds ratio [OR] = 0.78, 95% CI [0.37, 1.65]) and with discharge instructions (OR = 0.73, 95% CI [0.38, 1.42]) were broad and included values that would likely be clinically relevant, suggesting the study was underpowered to precisely estimate the effect of teach-back on these outcomes. A second study^51^ took place in an outpatient rheumatology clinic and evaluated differences in satisfaction among 75 patients randomized to receive a typed after-visit summary (AVS only), an AVS along with teach-back around discharge instructions (AVS+TB), or usual care. Satisfaction was measured across 5 domains of experience with the doctor (eg, easy to understand, confidence in the doctor’s ability to treat their condition) using a questionnaire similar to the CAHPS surveys, although origin was not stated by authors. Of the 54 patients who responded to the post-visit survey, more patients in the AVS+TB group reported “strongly agree” across all the satisfaction domains compared to those who received AVS only.

### Clinical Outcomes

Seven studies reported on changes in clinical (eg, hemoglobin A1c, perioperative blood pressure) or utilization (eg, hospital readmissions, ER visits) outcomes after teach-back. Overall, there was no consistent pattern of benefit to these outcomes with receipt of teach-back. Of the 3 studies that demonstrated a benefit in either adherence or knowledge,^26,52,57^ 2 reported improvements in clinical or utilization outcomes.^26,57^ One of these studies^57^ reported reducing surgical anxiety in 80 older adults who received teach-back in the perioperative setting. The other study^26^ reported improved adherence to self-care for heart failure and fewer hospital readmissions after multiple sessions of teach-back during an inpatient stay for heart failure. This finding was considered exploratory as we did not include studies reporting the effects of teach-back on clinical outcomes unless they also reported proximal or intermediate outcomes in accordance with the eligibility criteria.

### Certainty of Evidence (COE)

We conducted COE ratings for the proximal KQ1 outcomes identified in the included studies (Table 2). Overall, our COE was downgraded for some inconsistency in the direction of the effect and for high ROB of the included studies. For the 8 studies reporting knowledge outcomes specifically, we have very low COE due to inconsistency of the effect estimate and high ROB. The 5 studies reporting adherence outcomes consistently favored the intervention but were downgraded to moderate COE due to serious ROB. Across the studies reporting self-efficacy, the evidence was downgraded to very low COE considering the serious ROB as well as imprecision of effect estimates across included studies. Lastly, the patient satisfaction evidence was considered insufficient to draw conclusions due to the limited evidence.

Table 2 Certainty of Evidence

Outcome | Number of Studies | Findings | COE (Rationale)
Knowledge | 8 RCTs; (721 participants) | SMDs ranged from −0.98 to 1.76 (95% CIs ranged from −3.50 to 2.35) in 7 studies | Very low COE (downgraded for very serious ROB, and serious inconsistency)
Adherence | 7 RCTs; (613participants) | Summary SMD 0.73 (95% CI 0.47, 1.00); Z value for good surgical cooperation −2.08 (p = .038) | Moderate COE (downgraded for serious ROB)
Self-Efficacy | 5 RCTs; (412 participants) | Summary SMD 0.79 (95% CI 0.35, 1.23); Mean difference ranged from 1.63 to 8.47 (95% CI ranged from 0.94 to 9.51) depending on time point and subscale in 1 study | Very low COE (downgraded for very serious ROB, and serious imprecision)
Patient Satisfaction | 2 RCTs; (285 participants) | OR ranged from 0.68 to 0.94 depending on satisfaction component (95% CI ranged 0.39 to 1.57) in 1 study; Percent satisfaction in the intervention arm ranged from 78% to 89% and in the control arm ranged from 50% to 71% depending on the satisfaction component | Insufficient

Abbreviations. OR=odds ratio; SMD=standardized mean difference.

## KQ1B DOES THE EFFECT OF TEACH-BACK VARY BASED ON CLINICAL CONTEXT, INTERVENTION CHARACTERISTICS, OR PATIENT CHARACTERISTICS?

We found no pattern of difference in effectiveness of teach-back across inpatient versus outpatient settings and an insufficient number of studies to discern differences in treatment effect across specific clinical contexts. Similarly, there were no studies comparing teach-back delivered by different approaches to interventions delivered across content, interventionist, or mode.

Only 1 study^50^ enrolled solely patients with low health literacy, and it had a high ROB. Griffey et al (2015) evaluated the impact of teach-back for ED discharge instructions among adults with low health literacy as determined by a score of 6 or less on the Rapid Estimate of Adult Literacy in Medicine-Revised (REALM-R) tool.^50^ Teach-back in this study was found to improve patient knowledge of post-ED care instructions but not satisfaction or perceived comprehension.

Across the other 15 KQ1 studies, 2 described health literacy of study participants. One of these^51^ was a rheumatology clinic-based study and reported a mean arthritis REALM score of 61.83 (SD = 6.85) or above levels considered to be low literacy. The other^53^ was a study among hospitalized patients with obstructive lung disease, 74% of whom had adequate health literacy measured by the Short Test of Functional Health Literacy in Adults. Among all 16 RCTs analyzed for KQ1, participant education levels ranged from 28% to 85% with a high school or above education, with 2 studies^26,51^ reporting mean years of education (ranging from 5.65 to 15.8), and 3 studies^25,47,56^ not reporting education. Eight studies reported participant age and among 7^23,26,52,54–58^ (excluding the study on breastfeeding^48^), the average age of participants was over 50. The study on breastfeeding^48^ had an average participant age of 26.23 years. None of the identified studies reported subgroup analyses by education level, health literacy, or age. None of the studies reported rates of comorbid conditions likely to impair cognitive ability to acquire new health related information (eg, traumatic brain injury, cognitive impairment) within the enrolled populations.

## KQ2 WHAT IS THE EFFECT OF STRATEGIES TO INCREASE USE OF TEACH-BACK ON KEY IMPLEMENTATION OUTCOMES?

Seven studies^24,35–41,60^ described teach-back implementation within a health care setting, each reporting implementation activities and at least 1 implementation outcome. All 7 studies had a pre-post design, were conducted at a single site in the United States, and all but 1^37^ were conducted in the inpatient setting. The number of participants ranged from 19 nurses in a study based within a 20-bed adult oncology unit^41^ to 239 pediatric hospital-based staff members across unit types. All 7 studies self-labeled the approach used as “teach-back” and did not provide a comparison between implementation strategies. In 6^35,36,38–41^ of the 7 studies, nurses delivered or participated in the use of teach-back. and in the seventh^37^ teach-back was used by medical residents. A single study^41^ described the time commitment for teach-back and reported it to be 1 hour. This was also the only study which provided a separate teach-back intervention to caregivers.^41^

None of the 7 studies were identified by the authors as implementation studies nor were approaches to encouraging teach-back use described as “implementation strategies.” Rather, the studies were described as quality improvement (QI) projects, or in 1 case^39^ as a “system-wide, evidence-based practice project.” The most reported implementation strategies from the 9 PCORI strategy groupings^34^ were training staff, supporting practice change, and preparing for implementation (Figure 4). Specific training provided for clinicians delivering teach-back varied across studies, though often included health topic specific information (eg, heart failure^36^) in addition to teach-back itself across all studies. Three studies used existing tools to support teach-back implementation, including the AHRQ’s Health Literacy Universal Precautions Toolkit and the Always Use Teach-Back! Toolkit^38^; 10 Elements of Competence for Using Teach-back Effectively^40^; and Institute for Healthcare Improvement (2016) Always Events toolkit.^41^

Descriptions of key steps in the teach-back process were identified across the included KQ2 studies. The step in which the individual who delivered teach-back requested the patient or caregiver to describe their understanding in their own words was described in 4 studies.^36,37,40,41^ Four^35–37,41^ of the 7 studies included a description of additional rounds of teach-back as needed. Investigators included a so-called “teach-back initiation phrase”^10^ that frames a request for teach-back as an assessment of the clarity of the speaker’s communication rather a quiz or assessment of the recipient of the communication (eg, “can you tell me back what I said so I know that I explained the material clearly”).^36,37,41^

### Adoption

#### Summary of Findings

Three studies^35,36,39^ provided data on the adoption of teach-back. Two^35,39^ provided self-reported data indicating an increase in teach-back use after multi-strategy implementation efforts. The third^36^ reported low adoption as documented in discharge instructions.

#### Detailed Findings

One study that provided data on the adoption of teach-back was a system-wide, evidence-based practice project which sought to increase teach-back use with patients and families among 300 clinical staff at a 290-unit tertiary care pediatric hospital.^39^ Four implementation strategies were deployed over 24 months: (1) mobilizing site staff; (2) adapting to context; (3) preparing site for implementation; and (4) training site staff. Adoption was assessed via a survey of clinical staff members pre- and post-implementation. When asked “how often teach-back was currently used in practice,” a response of “always” was provided by 13% at baseline, 38% at 6–8 weeks, and 40% at 10–12 months. Teach-back was “sometimes” used by 70% at baseline, reducing to 60% at 6–8 weeks, and 59% at 10–12 months, while it was “never” used by 17% at baseline, reducing to 1% at 6–8 weeks, and 0% at 10–12 months.

The second QI project^35^ implemented teach-back among nurses for discharge-specific patient education in a 24-bed surgical unit by shifting the time of education to begin at admission and continue throughout hospitalization. Four implementation strategies were used: (1) adapting to context; (2) training of staff; (3) providing interactive assistance; and (4) support and supporting clinician practice change. Adoption was measured by self-report after completing discharge education for each patient at the end of the day and specified as the average number of teach-back questions per discharge. Adoption significantly increased from an average of 1.06 teach-back questions among 25 discharges (pre-implementation) to 5.5 across 10 discharges (at 1 month post-implementation), and to 4.5 across 12 discharges (at 6 months post-implementation) (p < .01).

The third QI project^36^ measured observed adoption of teach-back related to heart failure self-care management among 165 nurses working on 4 progressive care units. This study used strategies of preparing sites for implementation and training staff and clinicians. While it was noted that direct observations of the 28 nurses who requested additional individual coaching and observation were “positive,” only 9% of eligible discharge instructions included documentation of teach-back.

### Fidelity

#### Summary of Findings

Three studies^37,40,41^ noted an increase in fidelity to key teach-back features following an intervention to increase implementation. Two studies^37,40^ reported an observed evaluation of teach-back fidelity, while another^41^ evaluated fidelity via self-report of specific teach-back elements.

#### Detailed Findings

The first study^40^ was conducted in a large teaching hospital, where teach-back was implemented with patients and caregivers in the context of new medications. Six strategies were used: (1) mobilizing site staff for implementation; (2) adapting to context; (3) preparing sites for implementation; (4) training site staff; (5) supporting clinical practice change; and (6) engaging patients and families.^40^ Twenty-five nurses from a single medical unit provided pre- and post-implementation data on fidelity, measured by a direct observation tool. Multiple elements of effective teach-back significantly increased, including asking patients to explain in their own words (p < .001), using non-shaming and open-ended questions (p < .001), avoiding asking yes/no questions (p = .006), taking responsibility for making sure they were clear (p = .005), and documenting use and response to teach-back (p = .001). There was no change in clinician use of a caring tone, displaying comfortable body language, or including family members/caregivers. Overall, these nurses also self-reported increased use of teach-back during teaching sessions, conviction in importance of teach-back, and confidence in using teach-back (all p < .001).

The second study that examined fidelity reviewed recordings of clinical interactions to compare actual versus perceived teach-back use before and after the implementation intervention. Participants included 16 internal medicine and family medicine residents, and implementation strategies included training of staff/clinicians and supporting clinician practice change strategies.^37^ The proportion of residents using teach-back increased significantly from 2 of 16 (12.5%) before training to 10 of 16 (62.5%) 3 months post-implementation (p = .011). This compared to a perceived use of 60% pre-training as self-reported by residents (perceived use not reported after training).

The third study that evaluated fidelity^41^ evaluated self-reported fidelity. In a 20-bed oncology unit, teach-back for discharge instructions was implemented using a staff training strategy.^41^ Among 19 nurses surveyed, statistically significant increased use was reported over 50% of the time with the following teach-back practices: (1) using plain language; (2) taking responsibility to ensure clear communication; (3) using reader-friendly materials; and (4) documenting use of and patient response to teach-back method. Specific effect estimates and significance levels were not reported. Notably, a fourth article^38^ describing the implementation of educational coaching to increase teach-back reported increased use of teach-back elements but did not provide quantitative data to support this claim.

### Other

Three studies^38,40,41^ used the combination of outcome measures related to respondent conviction in the importance of using teach-back and their confidence in using teach-back from the Always Use Teach-Back! Toolkit.^61^ Each was scored on a 1 to 10 scale. These 3 studies^38,40,41^ reported increases in confidence with using teach-back after implementation, though there was some variation in baseline confidence and 1^38^ only reported a description of the percentage at baseline and post-intervention without reporting statistical significance. Changes in conviction in the importance of using teach-back was less consistent and baseline conviction was high in 2 studies.^38,41^ Two of these studies^38,41^ used only staff training and the third^40^ used 6 implementation strategies. A study^36^ deploying teach-back for heart failure self-care reported an increase in nurses’ knowledge of the teach-back method from pre- to post- implementation (N = 148; mean = 4.95 to 5.52, p < .001).

Figure 4 Implementation Strategies Heatmap

Heatmap of PCORI implementation strategies across the 7 studies included for KQ2 and brief summaries of relevant results from individual studies. All studies used the training staff implementation strategy. Three studies used tailor, iterate, adapt implementation strategy, or support practice change, or implementation prep strategies. Two studies reported interactive assistance or mobilize staff. One study used the engage patient implementation strategy.

| Train Staff | Tailor, Iterate, Adapt | Support Practice Change | Implementation Prep | Interactive Assistance | Mobilize Staff | Engage Patients | Outcomes
Burmeister, 2022^35^ | + | + | + | - | + | - | - | Adoption baseline, 1 month, 6 months: F ratio 13.15 (p < .01)
Caluya, 2021^36^ | + | - | - | + | + | - | - | Adoption post intervention: 9%
Feinberg, 2019^37^ | + | - | + | - | - | - | - | Fidelity baseline: 2/16; Post: 10/16 (p = .011)
Holman, 2019^38^ | + | - | - | - | - | - | - | Conviction in teach-back baseline: 75%; Post: 78%; Confidence in teach-back baseline 50%; Post: 78%
Klingbeil, 2018^39^ | + | + | - | + | - | + | - | Adoption (teach-back was used always) Pre: 13% 6-8 weeks: 38%; 10-12 months: 40%; Adoption (always checked for understanding) Pre: 13%; 6-8 weeks: 38%; 10-12 months: 40%
Prochnow, 2019^40^ | + | + | + | + | - | + | + | Conviction baseline mean: 5.0; 3 month mean: 9.5 (p < .0001); Confidence baseline mean: 2.2; 3 month mean: 8.6 (p < .0001); Fidelity baseline mean: 2.6; 3 month mean: 4.2 (p < .0001)
Scott, 2019^41^ | + | - | - | - | - | - | - | Conviction baseline mean: 8.94; post mean: 9.64; 1 month mean: 9.36; 3 month mean: 9.82; Confidence baseline mean: 7.83; post mean: 8.55; 1 month mean: 7.91; 3 month mean: 8.67; Fidelity to teach-back steps; Use caring tone of voice and attitude; Pre: 95%; Post: 100%; 3 months: 100%; Display comfortable body language, make eye contact, and sit down; Pre: 100%; Post: 100%; 3 months: 100%; Use plain language; Pre: 56%; Post: 55%; 3 months: 94%; Ask the patient to explain what they were told in their own words; Pre: 53%; Post: 53%; 3 months: 100%; Use nonshaming, open-ended questions; Pre: 94%; Post: 73%; 3 months: 72% Avoid asking yes or no questions; Pre: 33%; Post: 55%; 3 months: 61%; Take responsibility for being clear; Pre: 44%; Post: 45%; 3 months: 83%; Explain and recheck if the patient is unable to teach back; Pre: 64%; Post: 45%; 3 months: 91%; Use reader-friendly print materials to support learning; Pre: 33%; Post: 55%; 3 months: 50%; Document patient’s use of and response to the teach-back method; Pre: 44%; Post: 45%; 3 months: 56%

Notes: Plus sign (+) and minus sign (-) indicate the presence or absence of an implementation strategy in a given category.