# METHODS

## REGISTRATION AND REVIEW

A preregistered protocol for this review can be found on the PROSPERO international prospective register of systematic reviews (CRD42024596564 (https://www.crd.york.ac.uk/PROSPERO/view/CRD42024596564)). A draft version of this report was reviewed by external peer reviewers; their comments and author responses are located in the Appendix.

## KEY QUESTIONS AND ELIGIBILITY CRITERIA

The following KQs were the focus of this review:

- Key Question 1a (KQ1a): What is the effect of teach-back on patient and provider outcomes?
- Key Question 1b (KQ1b): Does the effect of teach-back vary based on clinical context (eg, hospital discharge, perioperative visit), intervention characteristic (eg, mode, content, interventionist), or patient characteristics (eg, education level, age)?
- Key Question 2 (KQ2): What is the effect of strategies to increase the use of teach-back on key implementation outcomes (eg, adoption, fidelity, sustainability)?

Study eligibility criteria are shown below (Table 1). For studies meeting these criteria, we established an a priori plan to focus abstraction and synthesis on those studies meeting criteria for higher levels of rigor (ie, Effective Practice and Organisation of Care [EPOC] designs^21^) depending on the volume of literature identified.

Table 1 Eligibility Criteria

Domain | Inclusion | Exclusion
Population | - KQ1: Adult patients or their caregivers; clinicians delivering care to adult patients; - KQ2: Health care organizations, clinics, teams, or clinicians; patients with or without their caregivers; - Clinician was defined as a health care provider (ie, MD, APP), pharmacist, psychologist, nurse, LCSW, or other professionally trained clinical personnel including post-license trainees such as medical residents if in the usual clinical care context; - Caregiver included any individual assisting a patient with health care due to a personal relationship rather than financial remuneration | KQ1/2: Pediatric patients (<18 years of age); patient populations <75% adult (≥18 years of age); lay health educators or community health workers and unpaid peer educators; students
Intervention | - KQ1: Single clinical synchronous, bi-directional encounter-based interactions which used teach-back by a clinician; must have included demonstration of understanding of medical information or skills by repeating the information back to the clinician with or without demonstration of specific skill or behavior; - Must have examined teach-back as a separate intervention for which effect could be evaluated independently of other health education approaches; - For studies conducted in the inpatient setting, each hospitalization was considered a single encounter of care; - KQ2: Implementation strategies employed to improve the uptake or use of teach-back by a clinician; - KQ1/2:; - Included if labeled as “teach-back” but did not include specific intervention description as outlined above; - “Teach-back” must have been described as part of the intervention as opposed to a strategy used to evaluate an intervention; - “Teach-back” must have occurred in the context of a real-time human interaction though initial education delivery may have been delivered via recorded information | - KQ1: Longitudinal programs (more than 1 encounter) that used teach-back over time through multiple patient interactions (eg, longitudinal self-management programs, case management); - KQ1/2: Interventions in which teach-back was delivered in combination with other significant educational strategies (eg, follow-up reinforcement after single encounter, home videos to support understanding after initial encounter) and could not have been independently evaluated from other educational interventions
Comparator | - KQ1: Usual care, other types of health education delivered by a clinician to a patient; - KQ2: No implementation support, comparison between implementation strategies, none | - KQ1: Studies that did not include a comparator; - KQ2: Not applicable
Outcomes | - KQ1: Proximal/intermediate outcomes; - Patient or caregiver outcomes (eg, knowledge, satisfaction, trust, adherence to recommended health behaviors, self-efficacy/confidence); - Provider outcomes (eg, job satisfaction, burnout); - KQ2: Implementation outcomes such as adoption, reach, adherence to teach-back/fidelity, sustained use | - KQ1: Studies that did not report proximal or intermediate outcomes; - KQ2: Studies that did not report implementation outcomes
Study Design | - KQ1: Randomized trials, non-randomized controlled trials, controlled before-after studies, interrupted time-series studies, prospective/retrospective controlled cohort studies; pilot studies; - KQ2: Controlled comparative or pre-post studies | - KQ1: Single-arm pre-post studies at the individual level, studies with no comparator group; - KQ2: Descriptive studies that only reported outcomes after intervention implementation without baseline or “pre” data; - KQ1/2: Qualitative studies, systematic reviews
Setting | - KQ1/2: Inpatient care, outpatient clinics; - KQ1/2: Any country | - KQ1/2: Non-health care settings; - KQ1/2: Research studies (ie, teach-back could not be related to informed consent for clinical research settings)
Language | KQ1/2: Any | Not applicable
Timing | KQ1/2: Studies published from 2018 onward or identified in prior systematic reviews | KQ1/2: Studies published prior to 2018 or identified in prior systematic reviews
Publication Type | KQ1/2: Full publications in a peer-reviewed journal | KQ1/2: Letters, opinion pieces, editorials, narrative reviews, dissertations, meeting abstracts, protocols without results, and non-peer-reviewed studies

Abbreviations. APP=Advanced practice provider; KQ=key question; MD=medical doctor; LCSW=licensed clinical social worker.

## SEARCHING AND SCREENING

To identify articles relevant to the key questions, a research librarian searched MEDLINE (via Ovid), Embase (via Elsevier), and CINAHL (via EBSCO) from January 1, 2018, to July 9, 2024 using terms for teach-back (eg, teach-back, closed loop) and patient education (see Appendix for complete search strategies). To ensure completeness, search strategies were developed in consultation with an expert medical librarian and peer reviewed by a second librarian in accordance with PRESS guidance.^22^ Additional citations were identified from hand-searching reference lists from 8 prior systematic reviews.^10,13–18,23^ Titles, abstracts, and full-text articles were independently reviewed by 2 investigators, and disagreements were resolved by a third reviewer or consensus. We attempted to include all identified citations in our review regardless of language. If we were unable to identify a high-quality translation or a team member fluent in the relevant language, it was counted at the highest level of citation screening possible without undergoing data abstraction and inclusion in the synthesis.

## DATA ABSTRACTION AND RISK OF BIAS ASSESSMENT

Study characteristics were abstracted into Covidence independently by 2 reviewers. Quantitative results data were abstracted into Microsoft Excel by 1 reviewer and over-read by a second reviewer. Disagreements were resolved by consensus or by obtaining a third reviewer’s opinion when consensus could not be reached.

Across included studies, we abstracted characteristics of teach-back interventions, including setting (eg, inpatient or outpatient), clinical context (eg, hospital discharge, relevant health condition), communication modality (eg, in-person versus virtual), interventionist characteristics (eg, profession, age), concurrent educational strategies used (if any), and time spent on teach-back. We also abstracted details about the comparator group and all reported outcomes. Implementation outcomes were identified using established definitions. Specifically, adoption was defined as “the intention, initial decision, or action to try to employ an innovation” and fidelity was defined as “the degree to which an intervention was implemented as it was prescribed.”^24^ We prioritized results based on the most complete and appropriately analyzed data. When critical data were missing or unclear in published reports, we requested clarification or supplemental data from the study authors through e-mail.^25–27^ Given that sufficient studies were identified for KQ1, we prioritized EPOC studies for this KQ. There were limited eligible articles for KQ2, so we abstracted all identified.

We used the Cochrane RoB-2 tool to assess risk of bias (ROB) for randomized trials identified for KQ1.^28^ This tool included the following domains: (1) bias arising from the randomization process; (2) bias due to deviations from intended interventions; (3) bias due to missing outcome data; (4) bias in measurement of the outcome; (5) bias in selection of the reported result; and (6) overall ROB (options were low, some concerns, or high ROB) (see Appendix for ROB ratings).

## SYNTHESIS

We constructed summary tables to describe key study characteristics of the primary studies. We then determined the feasibility of completing a quantitative synthesis (ie, meta-analysis) to estimate summary effects. We made this assessment based on the volume of relevant literature, conceptual homogeneity of the studies, and completeness of the reported results. When a study reported more than 1 knowledge subscale measure in addition to an overall measure, we examined the overall measure only. When a study included multiple comparison arms, we limited our analysis to the comparison that allowed isolation of teach-back effect. We aggregated outcomes via meta-analysis when at least 3 studies reported the same outcome, based on the rationale that 1-2 studies would not provide adequate evidence for summary effects.

In general, we used standardized mean differences (SMD; Hedges’ g) for combining study results because included studies employed different measures of the same construct. SMD magnitude is standardly categorized as follows: small (0.2), medium (0.5), and large (0.8).^29^ Studies reported a mix of dichotomous outcomes and continuous outcomes. When reasonable to conclude that dichotomous and continuous data measured a conceptually similar underlying construct, effect sizes for dichotomous outcomes were transformed into SMDs using the Cox transformation to enable synthesis of all outcome data.^30^ If measured constructs were considered not sufficiently conceptually similar, dichotomous and continuous effect data were separately synthesized.

As all meta-analyses included fewer than 20 studies, we used the Knapp-Hartung approach to adjust model standard errors.^31,32^ We employed multilevel meta-analysis models when studies reported multiple effect estimates (ie, group differences at multiple time points, comparisons of multiple treatment groups to control). We evaluated statistical heterogeneity using visual inspection of forest plots and 95% prediction intervals (PI). Meta-analyses were conducted using the metafor package for R (R Foundation for Statistical Computing, Vienna, Austria).^33^

Too few studies were available for us to examine whether intervention or study characteristics explained differences in the effects of teach-back across studies. In addition, none of the included studies provided outcomes separately for patients with key characteristics (eg, age, sex, race, and ethnicity). We described the representation of patient population when available.

When quantitative synthesis was not feasible, we synthesized the data narratively to document and identify patterns in efficacy of the interventions across settings and outcome categories. We focused on evidence from higher quality studies as determined by the ROB assessment with more precise estimates of effect. We explored potential reasons for inconsistency in treatment effects across studies by evaluating differences in the intervention, comparator, and outcome definitions.

To identify implementation strategies for studies eligible for KQ2, we used the definitions from the 9 PCORI strategy groupings^34^ (see Appendix for data abstraction form and categorization of implementation strategies).

### Strength of Evidence

The strength of evidence was assessed using the approach described by Grading of Recommendations Assessment, Development and Evaluation (GRADE). We limited GRADE ratings to those outcomes identified by our operational partners and members of the technical expert panel (TEP) as critical to policy and clinical decision-making. In brief, the GRADE approach required assessment of 4 domains: (1) ROB; (2) consistency; (3) directness; and (4) precision. Additional domains used when appropriate included coherence, dose-response association, impact of plausible residual confounders, strength of association (magnitude of effect), and publication bias. These domains were considered qualitatively and a summary rating was assigned, after discussion amongst 2 investigators, as insufficient, very low, low, moderate, or high strength of evidence.