# BACKGROUND

For decades, patient- and family-centered care has been considered a hallmark of high-quality care in the United States.^1,2^ Rather than assuming the hierarchical roles of the traditional medical model where the “doctor knows best,” health care users and health care professionals engage as partners.^3–5^ Meaningful partnership requires health care users to understand and use conveyed information.^6,7^ Health care organizations and providers have a responsibility to support patients in the acquisition of information pertinent to their health. This responsibility has been named organizational health literacy (as opposed to personal health literacy) and is defined as “the degree to which organizations equitably enable individuals to find, understand, and use information and services to inform health-related decisions and actions for themselves and others.”^8^ Health literacy, encompassing both personal and organizational health literacy, is a national priority and is addressed in 6 Healthy People objectives of the US Department of Health and Human Services’ Healthy People 2030 initiative.^8,9^ Within VHA, the National Center for Health Promotion and Disease Prevention’s Patient-Centered Learning Program is leading efforts to address organizational health literacy.

One method of organizational health literacy is a strategy known as teach-back. Teach-back is intended to promote patient and family understanding of health information, as well as promote patient adherence and adoption of health behaviors. It involves a health care professional providing information (verbally or by demonstration), followed by a request for the recipient of the information to repeat back or redemonstrate the information, and the recipient completing this task.^10^ Some definitions include an additional step of providing clarification information if patients do not demonstrate understanding with additional cycles of teach-back. As a method of communication, teach-back could be expected to impact a variety of proximal (eg, recipient understanding), intermediate (eg, self-efficacy), or distal (eg, clinical readmissions) outcomes (see Appendix).^11,12^ As such, it is considered a key strategy for health care organizations to advance organizational health literacy and has been identified by the Patient-Centered Learning Program as a promising approach to promote VHA organizational literacy and Veteran education . However, both the effectiveness of the approach and the optimal real-world implementation methods for teach-back in clinical settings are incompletely characterized. Prior systematic reviews of teach-back effectiveness have focused on specific diseases like heart failure,^13^ chronic kidney disease,^14^ and cancer,^15^ or on specific outcomes such as self-management^16^ or readmissions.^17,18^ Three recent systematic reviews^10,19,20^ have taken a broader view. One^10^ focused on the range of teach-back definitions existing in the literature and health care professional and patient perceptions of teach-back.^10^ Of the other 2,^19,20^ both examined effectiveness, with the most recent literature search conducted in July of 2019, and 1^20^ also systematically evaluated implementation strategies. These reviews found that most studies of teach-back reported positive findings for a variety of outcomes, but the quality of most evidence was not high, and studies did not require a comparator to be included in the review (limiting the ability to draw conclusions regarding effectiveness of the intervention). Moreover, there was limited evidence on implementation strategies. Given the limitations of prior reviews and the additional literature produced since their publication, an updated review is warranted.

This systematic review aimed to provide an updated synthesis of existing literature on teach-back effectiveness and implementation strategies. Our key questions (KQ) were: (1) What is the effect of teach-back on patient and provider outcomes? (2) Does the effect of teach-back vary by clinical context, intervention characteristic, or patient characteristics? and (3) What is the effect of strategies to increase the use of teach-back on key implementation outcomes? Findings of this review will inform efforts of the VHA’s National Center for Health Promotion and Disease Prevention as they seek to optimize agency approaches to enhance the quality and impact of patient education.