# Appendix

## SEARCH STRATEGIES

### Database: MEDLINE (via Ovid)

Search date: 7/9/2024

Note: Ovid MEDLINE ALL 1946 to July 08, 2024

Search Set + Description | Search Strategy | # Results
#1; Teach-back terms | exp teach-back communication/ or (teach-back or “teach back” or “repeat back” or “repeats back” or “repeating back” or “repeated back” or “return demonstration” or “return demonstrations” or “show me” or show-me or “show back” or show-back or ask-offer-ask or “ask offer ask” or ask-tell-ask or “ask tell ask” or teach-to-goal or “teach to goal”).ti,ab. or (teach* adj2 back).ti,ab. or (interactive adj2 (communicat* or feedback) adj2 loop).ti,ab. or ((closed-loop or “closed loop” or “closing the loop” or closed-cycle or “closed cycle” or “closing the cycle” or “feedback loop”) adj4 communicat*).ti,ab. or ((repeat* or restat*) adj2 (instruction* or information)).ti,ab. or (closing adj2 loop).ti,ab. | 2564
#2; Patient education or caregiver education or family education terms | exp patient education/ or exp caregivers/ed or exp adult children/ed or exp spouses/ed or ((patient or patients or in-patient or in-patients or inpatient or inpatients or outpatient or outpatients or out-patient or out-patients or caregiver or caregivers or carer or carers or “care giver” or “care givers” or caretaker or caretakers or “care taker” or “care takers” or family or families or relatives or spouse or spouses or spousal or partner or partners or “adult child” or “adult children” or “significant other” or “significant others”) adj4 (educat* or train or trains or trained or training or trainings or teach or teaches or taught or teaching or teachings)).ti,ab. | 199363
#3; Knowledge check terms | ((confirm* or check* or test or tests or tested or testing or demo or demonstrat* or clarify or clarifies or clarifying or clarified or clarification) adj3 (understand* or knowledge or skills or comprehen* or ability or abilities or skill or skills or recall)).ti,ab. | 104134
#4; Own words terms | (“their own words”).ti,ab. | 637
#5 | 3 or 4 | 1047600
#6 | 2 and 5 | 2197
#7 | 1 or 6 | 4728
#8; Exclude animal studies | 7 not (exp animals/ not exp humans/) | 4627
#9; Exclude study designs | 8 not (case reports OR editorial OR letter OR comment OR congress).pt. | 4383
#10; Date limit | limit 9 to yr=“2018 -Current” | 1742

### Database: Embase (via Elsevier)

Search date: 7/9/2024

Note: Search from the Results page

Search Set + Description | Search Strategy | # Results
#1; Teach-back terms | (‘teach back’ OR ‘repeat back’ OR ‘repeats back’ OR ‘repeating back’ OR ‘repeated back’ OR ‘return demonstration’ OR ‘return demonstrations’ OR ‘show me’ OR ‘show back’ OR ‘ask offer ask’ OR ‘ask tell ask’ OR ‘teach to goal’):ti,ab OR (teach* NEAR/2 back):ti,ab OR (interactive NEAR/2 (communicat* OR feedback) NEAR/2 loop):ti,ab OR ((‘closed loop’ OR ‘closing the loop’ OR ‘closed cycle’ OR ‘closing the cycle’ OR ‘feedback loop’) NEAR/4 communicat*):ti,ab OR ((repeat* OR restat*) NEAR/2 (instruction* OR information)):ti,ab OR (closing NEAR/2 loop):ti,ab | 3646
#2; Patient education OR caregiver education OR family education terms | ‘patient education’/exp OR ((patient OR patients OR ‘in-patient’ OR ‘in-patients’ OR inpatient OR inpatients OR outpatient OR outpatients OR ‘out-patient’ OR ‘outpatients’ OR caregiver OR caregivers OR carer OR carers OR ‘care giver’ OR ‘care givers’ OR caretaker OR caretakers OR ‘care taker’ OR ‘care takers’ OR family OR families OR relatives OR spouse OR spouses OR spousal OR partner OR partners OR ‘adult child’ OR ‘adult children’ OR ‘significant other’ OR ‘significant others’) NEAR/4 (educat* OR train OR trains OR trained OR training OR trainings OR teach OR teaches OR taught OR teaching OR teachings)):ti,ab | 288939
#3; Knowledge check terms | ((confirm* OR check* OR test OR tests OR tested OR testing OR demo OR demonstrat* OR clarify OR clarifies OR clarifying OR clarified OR clarification) NEAR/3 (understand* OR knowledge OR skills OR comprehen* OR ability OR abilities OR skill OR skills OR recall)):ti,ab | 134994
#4; Own words terms | (‘their own words’):ti,ab | 897
#5 | #3 OR #4 | 135875
#6 | #2 AND #5 | 3467
#7 | #1 OR #6 | 7047
#8; Exclude animal studies | #7 AND [humans]/lim | 6170
#9; Exclude study designs | #8 NOT (‘case report’/exp OR ‘case study’/exp OR ‘editorial’/exp OR [editorial]/lim OR ‘letter’/exp OR [letter]/lim OR ‘note’/exp OR [note]/lim OR [conference abstract]/lim OR ‘conference abstract’/exp OR ‘conference abstract’/it) | 3824
#10; Date limit | #9 AND [01-01-2018]/sd | 1671

### Database: CINAHL Complete (via EBSCO)

Search date: 7/9/2024

Search Set + Description | Search Strategy | # Results
#1; Teach-back terms | ((TI teach-back OR AB teach-back) OR (TI “teach back” OR AB “teach back”) OR (TI “repeat back” OR AB “repeat back”) OR (TI “repeats back” OR AB “repeats back”) OR (TI “repeating back” OR AB “repeating back”) OR (TI “repeated back” OR AB “repeated back”) OR (TI “return demonstration” OR AB “return demonstration”) OR (TI “return demonstrations” OR AB “return demonstrations”) OR (TI “show me” OR AB “show me”) OR (TI show-me OR AB show-me) OR (TI “show back” OR AB “show back”) OR (TI show-back OR AB show-back) OR (TI ask-offer-ask OR AB ask-offer-ask) OR (TI “ask offer ask” OR AB “ask offer ask”) OR (TI ask-tell-ask OR AB ask-tell-ask) OR (TI “ask tell ask” OR AB “ask tell ask”) OR (TI teach-to-goal OR AB teach-to-goal) OR (TI “teach to goal” OR AB “teach to goal”)) OR ((TI teach* OR AB teach*) N2 (TI back OR AB back)) OR ((TI interactive OR AB interactive) N2 ((TI communicat* OR AB communicat*) OR (TI feedback OR AB feedback)) N2 (TI loop OR AB loop)) OR (((TI closed-loop OR AB closed-loop) OR (TI “closed loop” OR AB “closed loop”) OR (TI “closing the loop” OR AB “closing the loop”) OR (TI closed-cycle OR AB closed-cycle) OR (TI “closed cycle” OR AB “closed cycle”) OR (TI “closing the cycle” OR AB “closing the cycle”) OR (TI “feedback loop” OR AB “feedback loop”)) N4 (TI communicat* OR AB communicat*)) OR (((TI repeat* OR AB repeat*) OR (TI restat* OR AB restat*)) N2 ((TI instruction* OR AB instruction*) OR (TI information OR AB information))) OR ((TI closing OR AB closing) N2 (TI loop OR AB loop)) | 1500
#2; Patient education or caregiver education or family education terms | (MH “Patient Education+”) OR (MH “Caregivers/ED”) OR (MH “Spouses/ED”) OR (MH “Family/ED”) OR (MH “Adult Children/ED”) OR (((TI patient OR AB patient) OR (TI patients OR AB patients) OR (TI in-patient OR AB in-patient) OR (TI in-patients OR AB in-patients) OR (TI inpatient OR AB inpatient) OR (TI inpatients OR AB inpatients) OR (TI outpatient OR AB outpatient) OR (TI outpatients OR AB outpatients) OR (TI out-patient OR AB out-patient) OR (TI out-patients OR AB out-patients) OR (TI caregiver OR AB caregiver) OR (TI caregivers OR AB caregivers) OR (TI carer OR AB carer) OR (TI carers OR AB carers) OR (TI “care giver” OR AB “care giver”) OR (TI “care givers” OR AB “care givers”) OR (TI caretaker OR AB caretaker) OR (TI caretakers OR AB caretakers) OR (TI “care taker” OR AB “care taker”) OR (TI “care takers” OR AB “care takers”) OR (TI family OR AB family) OR (TI families OR AB families) OR (TI relatives OR AB relatives) OR (TI spouse OR AB spouse) OR (TI spouses OR AB spouses) OR (TI spousal OR AB spousal) OR (TI partner OR AB partner) OR (TI partners OR AB partners) OR (TI “adult child” OR AB “adult child”) OR (TI “adult children” OR AB “adult children”) OR (TI “significant other” OR AB “significant other”) OR (TI “significant others” OR AB “significant others”)) N4 ((TI educat* OR AB educat*) OR (TI train OR AB train) OR (TI trains OR AB trains) OR (TI trained OR AB trained) OR (TI training OR AB training) OR (TI trainings OR AB trainings) OR (TI teach OR AB teach) OR (TI teaches OR AB teaches) OR (TI taught OR AB taught) OR (TI teaching OR AB teaching) OR (TI teachings OR AB teachings))) | 150260
#3; Knowledge check terms | (((TI confirm* OR AB confirm*) OR (TI check* OR AB check*) OR (TI test OR AB test) OR (TI tests OR AB tests) OR (TI tested OR AB tested) OR (TI testing OR AB testing) OR (TI demo OR AB demo) OR (TI demonstrat* OR AB demonstrat*) OR (TI clarify OR AB clarify) OR (TI clarifies OR AB clarifies) OR (TI clarifying OR AB clarifying) OR (TI clarified OR AB clarified) OR (TI clarification OR AB clarification)) N3 ((TI understand* OR AB understand*) OR (TI knowledge OR AB knowledge) OR (TI skills OR AB skills) OR (TI comprehen* OR AB comprehen*) OR (TI ability OR AB ability) OR (TI abilities OR AB abilities) OR (TI skill OR AB skill) OR (TI skills OR AB skills) OR (TI recall OR AB recall))) | 29386
#4; Own words terms | ((TI “their own words” OR AB “their own words”)) | 806
#5 | S3 OR S4 | 30184
#6 | S2 AND S5 | 1835
#7 | S1 OR S6 | 3295
#8; Exclude study designs | S7 NOT PT ( Abstract OR Book OR Book Chapter OR Book Review OR Case Study OR Commentary OR Editorial OR Letter OR Masters Thesis OR Pamphlet OR Pamphlet Chapter OR Poetry ) | 3012
#9; Date limit | Limiters - Publication Date: 20180101-20251231 | 1144

## STUDIES EXCLUDED DURING FULL-TEXT SCREENING

Citation | Exclude Reason
Rydman, 1999^1^ | 7
Anonymous, 2022^2^ | 3
Anonymous, 2024^3^ | 3
Anonymous, 2024^4^ | 3
Abbasi Abianeh, 2020^5^ | 2
Abhilash, 2022^6^ | 2
Ahmadidarrehsima, 2020^7^ | 1
Ahmadidarrehsima, 2016^8^ | 1
Al-Kharouf, 2023^9^ | 3
Al-Kharouf, 2023^10^ | 1
Andreoli, 2021^11^ | 4
Anonymous, 2019^12^ | 3
Antrum, 2019^13^ | 7
Arceo, 2018^14^ | 2
Arnold, 2019^15^ | 6
Awoke, 2019^16^ | 1
Barsuk, 2021^17^ | 1
Barsuk, 2019^18^ | 1
Basheti, 2019^19^ | 2
Bates, 2014^20^ | 1
Bhatt, 2018^21^ | 1
Bickes, 2021^22^ | 5
Borzou, 2020^23^ | 1
Boyde, 2018^24^ | 1
Cabilan, 2019^25^ | 5
Catal, 2023^26^ | 1
Cheng, 2023^27^ | 1
Coulter, 2018^28^ | 2
Dinh, 2019^29^ | 2
Durden, 2018^30^ | 3
Edison, 2020^31^ | 3
Fruijtier, 2023^32^ | 4
George, 2018^33^ | 5
Ghiasvand, 2017^34^ | 1
Hahn-Goldberg, 2021^35^ | 1
Hasanpour Dehkordi, 2021^36^ | 6
Hodges, 2021^37^ | 2
Holcomb, 2022^38^ | 4
Hong, 2019^39^ | 1
Hong, 2020^40^ | 1
Huang, 2023^41^ | 1
Imanipour, 2022^42^ | 1
Jabbar, 2021^43^ | 2
Jaimalai, 2024^44^ | 1
Jangjoo, 2023^45^ | 1
Jia, 2024^46^ | 1
Kapoor, 2018^47^ | 2
Kardine, 2023^48^ | 3
Kennedy, 2021^49^ | 4
Kesanen, 2019^50^ | 1
khaja, 2018^51^ | 2
Khudhair, 2022^52^ | 1
Kim, 2020^53^ | 3
Kindratt, 2020^54^ | 2
Konstantinos, 2018^55^ | 3
Kopelson, 2024^56^ | 4
Kul Uctu, 2020^57^ | 2
Kul Uctu, 2023^58^ | 1
Kumar, 2022^59^ | 8
Kwaitana, 2024^60^ | 2
Lampert, 2019^61^ | 1
Lata, 2022^62^ | 5
Lay, 2019^63^ | 1
Lee, 2018^64^ | 1
Lemcke, 2022^65^ | 1
Li, 2023^66^ | 1
Lima, 2023^67^ | 1
Lin, 2023^68^ | 1
Lindblom, 2023^69^ | 2
Liu, 2018^70^ | 1
Lopez, 2023^71^ | 2
Makiling, 2020^72^ | 1
Maleki, 2022^73^ | 1
Maricoto, 2019^74^ | 2
Marshall, 2022^75^ | 2
McDaniels, 2020^76^ | 1
McInerney, 2020^77^ | 4
McKerrocher, 2023^78^ | 2
Milazi, 2021^79^ | 1
Miller, 2021^80^ | 1
Mohammadi, 2021^81^ | 1
Molazem, 2018^82^ | 1
Morony, 2018^83^ | 4
Muscat, 2021^84^ | 2
Muyiwa-Ojo, 2018^85^ | 2
Naji, 2023^86^ | 1
Nazir, 2020^87^ | 1
Newman, 2019^88^ | 1
Nguyen, 2018^89^ | 2
Nickles, 2020^90^ | 2
Nimri, 2018^91^ | 1
Nimri, 2017^92^ | 1
Orlandin, 2018^93^ | 1
Orr, 2018^94^ | 3
Oyesanya, 2020^95^ | 1
Pandurangan, 2018^96^ | 2
Pei, 2023^97^ | 1
Perreault, 2021^98^ | 3
Peter, 2015^99^ | 6
Pinsker, 2021^100^ | 1
Porter, 2019^101^ | 1
Roopavathy, 2023^102^ | 1
Rosdahl, 2021^103^ | 1
Ryan-Madonna, 2019^104^ | 2
Sanchez-Nieto, 2022^105^ | 2
Seely, 2022^106^ | 4
Shichijo, 2023^107^ | 3
Shigli, 2020^108^ | 3
Zhang Simei, 2024^109^ | 1
Stuart, 2019^110^ | 1
Subramanian, 2020^111^ | 1
Subramanya, 2021^112^ | 1
Thakur, 2021^113^ | 2
Thomas, 2018^114^ | 3
Thomas, 2019^115^ | 2
Thomas, 2021^116^ | 2
Trela, 2022^117^ | 2
Ulrich, 2022^118^ | 4
Uzun, 2023^119^ | 1
van der Giessen, 2021^120^ | 1
Vazquez-Gonzalez, 2023^121^ | 1
Voelliger, 2021^122^ | 2
Wang, 2024^123^ | 1
Wang, 2023^124^ | 1
Wang, 2024^125^ | 1
White, 2013^126^ | 5
Xia, 2024^127^ | 1
Yilmaz, 2023^128^ | 1
Yousif, 2021^129^ | 2
Zimenkovsky, 2018^130^ | 1
김남희, 2018^131^ | 1
张玉梅, 2018^132^ | 1
杨建梅, 2023^133^ | 1
欧瑞肖, 2022^134^ | 4
潘卫宇, 2022^135^ | 1
王莹, 2021^136^ | 1

Notes. Exclusion reasons: 1= Ineligible intervention, 2= Ineligible study design, 3= Ineligible publication type, 4= Ineligible patient population, 5= Ineligible comparator, 6= Ineligible outcomes, 7= Could not find full text, 8= Ineligible setting

1 Rydman RJ . Evaluating the Outcomes of Two Teaching Methods of Breath Actuated Inhaler in an Inner City Asthmas Clinic. 1999. Journal of Medical Systems, Vol 23, 349–156.10587915
2 Anonymous. Researchers Offer Definition of Teach-Back for Surgical Informed Consent. Medical Ethics Advisor. 2022;38(7):1–1.
3 Anonymous. The Effect of Teach-Back on Readmission Rates in Rehabilitation Patients. Rehabilitation nursing : the official journal of the Association of Rehabilitation Nurses. 2024;49(2):E7–E8.38421878
4 Anonymous. Show me the money. Journal of the Irish Dental Association. 2024;70(2):65–65.
5 Abbasi Abianeh N, Abdollah Zargar S, Amirkhani A, Adelipouramlash A. The effect of self-care education through teach back method on the quality of life in hemodialysis patients. Nephrologie et Therapeutique. 2020;16(4):197–200.32532600
6 Abhilash, Diana. A Study to Assess the Effectiveness of Structured Teaching Programme (STP) to the Care Givers Regarding Pre and Post Operative Care on Knowledge and Practice of Clients, Undergoing Cataract Surgery at Selected Camps Conducted in Bidar. International Journal of Nursing Education. 2022;14(2):18–23.
7 Ahmadidarrehsima S, Bidmeshki EA, Rahnama M, . The Effect of Self-Management Education by the Teach-Back Method on Uncertainty of Patients with Breast Cancer: a Quasi-Experimental Study. Journal of Cancer Education. 2020;35(2):366–372.30680649
8 Ahmadidarrehsima S, Rahnama M, Afshari M, Asadi Bidmeshki E. Effectiveness of Teach-Back Self-Management Training Program on Happiness of Breast Cancer Patients. Asian Pac J Cancer Prev. 2016;17(10):4555–4561.27892662
9 Al-Kharouf M, Abdeljalil M, Obeidat N, . Video-based teach-to-goal intervention on inhaler technique on adults with asthma and COPD: a randomized controlled trial. Jordan Journal of Pharmaceutical Sciences. 2023;16(2):479.
10 Al-Kharouf MS, Abdeljalil MH, Obeidat NM, . Video-based teach-to-goal intervention on inhaler technique on adults with asthma and COPD: A randomized controlled trial. PloS One. 2023;18(6 JUNE).
11 Andreoli A, Klingbeil C. Implementing Pediatric Transition Education Initiative During Inpatient Admissions in the Epilepsy Monitoring Unit. Journal of Pediatric Nursing. 2021;57:50–55.33242830
12 Anonymous. Improving Patient and Caregiver New Medication Education Using an Innovative Teach-back Toolkit. Journal of Nursing Care Quality. 2019;34(2):E13–E14.30789486
13 Antrum V-A, Catanzaro AM, Zewe J, . The Teach-Back Method to Improve Patients’ Perception of Nurse Communication. Med-Surg Matters. 2019;28(5):4–7.
14 Arceo JM. Adult Patients with Schizophrenia and Noncompliance with Antipsychotics. Adult Patients with Schizophrenia & Noncompliance with Antipsychotics. 2018:1–1.
15 Arnold CL, Rademaker AW, Morris JD, . Follow-up approaches to a health literacy intervention to increase colorectal cancer screening in rural community clinics: A randomized controlled trial. Cancer. 2019;125(20):3615–3622.31355924
16 Awoke MS, Baptiste DL, Davidson P, . A quasi-experimental study examining a nurse-led education program to improve knowledge, self-care, and reduce readmission for individuals with heart failure. Contemporary Nurse. 2019;55(1):15–26.30632457
17 Barsuk JH, Cohen ER, Cameron KA, . Short-Term Retention of Patient and Caregiver Ventricular Assist Device Self-Care Skills After Simulation-Based Mastery Learning. Clinical Simulation in Nursing. 2021;53:1–9.33747259
18 Barsuk JH, Wilcox JE, Cohen ER, . Simulation-Based Mastery Learning Improves Patient and Caregiver Ventricular Assist Device Self-Care Skills: A Randomized Pilot Trial. Circulation. Cardiovascular Quality & Outcomes. 2019;12(10):e005794.31601111
19 Basheti IA, Salhi YB, Basheti MM, . Role of the pharmacist in improving inhaler technique and asthma management in rural areas in Jordan. Clinical Pharmacology. 2019;11:103–116.31413644
20 Bates OL, O’Connor N, Dunn D, Hasenau SM. Applying STAAR interventions in incremental bundles: improving post-CABG surgical patient care. Worldviews Evid Based Nurs. 2014;11(2):89–97.24720698
21 Bhatt S, McCurdy CE, Liew D, Russell DM. Effect of warfarin education on patient knowledge and anticoagulation control: a randomised controlled trial. Journal of Pharmacy Practice and Research. 2018;48(6):516–521.
22 Bickes D, Jennings K, Feinberg I. Health Literacy Strategies to Engage Cancer Patients and Caregivers. Journal of Oncology Navigation & Survivorship. 2021;12(3):82–85.
23 Borzou SR, Rasoli M, Khalili Z, Tapak L. Comparison of group discussion and teach back selfcare education effects on knowledge, attitude, and performance of hemodialysis patients. Nephro-Urology Monthly. 2020;12(3):1–7.
24 Boyde M, Peters R, New N, . Self-care educational intervention to reduce hospitalisations in heart failure: A randomised controlled trial. European Journal of Cardiovascular Nursing. 2018;17(2):178–185.28832179
25 Cabilan CJ, Boyde M, Currey E. The effectiveness of pharmacist- led discharge medication counselling in the emergency department (ExPLAIN): A pilot quasi-experimental study. Patient Education and Counseling. 2019;102(6):1157–1163.30712945
26 Catal AT, Cebeci F. The effect of discharge training with the teach-back method on post-discharge challenges in lumbar disc herniation patients: A quasi-experimental study. International Journal of Orthopaedic and Trauma Nursing. 2023;50:101020.37437463
27 Cheng GZ, Chen A, Xin Y, Ni QQ. Using the teach-back method to improve postpartum maternal-infant health among women with limited maternal health literacy: a randomized controlled study. BMC Pregnancy and Childbirth. 2023;23(1):13.36624440
28 Coulter KJ. Standardized Follow-Ups Lower HbA1c in Adults With Type 2 Diabetes Living in a Rural Community: A Pilot Study. Journal of Doctoral Nursing Practice. 2018;11(1):16–24.32745040
29 Dinh HTT, Bonner A, Ramsbotham J, Clark R. Cluster randomized controlled trial testing the effectiveness of a self-management intervention using the teach-back method for people with heart failure. Nursing & Health Sciences. 2019;21(4):436–444.31190459
30 Durden H. Using Teach-Back Guided Patient Education to Improve Hospital Consumer Assessment of Healthcare Providers and Systems (HCAHPS) Scores. Using Teach-Back Guided Patient Education to Improve Hospital Consumer Assessment of Healthcare Providers & Systems (Hcahps) Scores. 2018:1–1.
31 Edison K. Telehealth and Outreach in the Post COVID-19 World: The MU Show-Me ECHO Program as a National Model. Missouri Medicine. 2020;117(3):214–215.32636552
32 Fruijtier AD, van der Schaar J, van Maurik IS, . Identifying best practices for disclosure of amyloid imaging results: A randomized controlled trial. Alzheimer’s & Dementia. 2023;19(1):285–295.
33 George NE, Sunny S, Sam AM, . Effect of medication related educational interventions on improving medication adherence in patients with type 2 diabetes mellitus. Asian Journal of Pharmaceutical and Clinical Research. 2018;11(1):167–170.
34 Ghiasvand F, Riazi H, Hajian S, . The effect of a self-care program based on the teach back method on the postpartum quality of life. Electron Physician. 2017;9(4):4180–4189.28607653
35 Hahn-Goldberg S, Huynh T, Chaput A, . Implementation, spread and impact of the Patient Oriented Discharge Summary (PODS) across Ontario hospitals: a mixed methods evaluation. BMC Health Services Research. 2021;21(1):361.33865385
36 Hasanpour Dehkordi A, Ebrahimi-Dehkordi S, Banitalebi-Dehkordi F, . The effect of teach-back training intervention of breathing exercise on the level of dyspnea, six-minutes walking test and FEV1/FVC ratio in patients with chronic obstructive pulmonary disease; a randomized controlled trial. Expert Review of Respiratory Medicine. 2021;15(1):161–169.32921199
37 Hodges R, Stepien S, Kim LY. Quality Improvement: Using Teach-Back to Improve Patient Satisfaction during Discharge in the Emergency Department. Journal of Emergency Nursing. 2021;47(6):870–878.34215436
38 Holcomb J, Ferguson GM, Thornton L, Highfield L. Development, implementation, and evaluation of Teach Back curriculum for community health workers. Frontiers in Medicine. 2022;9:918686.36405583
39 Hong Y-R, Cardel M, Suk R, . Teach-Back Experience and Hospitalization Risk Among Patients with Ambulatory Care Sensitive Conditions: a Matched Cohort Study. JGIM: Journal of General Internal Medicine. 2019;34(10):2176–2184.31385206
40 Hong YR, Huo J, Jo A, . Association of Patient-Provider Teach-Back Communication with Diabetic Outcomes: A Cohort Study. Journal of the American Board of Family Medicine: JABFM. 2020;33(6):903–912.33219069
41 Huang J, Lin X, Xiong D, . Impact of the teach-back method on caregiver outcomes using the “Timing it Right” framework for hemodialysis patients. Frontiers in Public Health. 2023;11:1123006.37427278
42 Imanipour M, Molazem Z, Rakhshan M, Fallahi MJ. Evaluation of the Effectiveness of Teach-back Training on Asthma Control Indicators. Tanaffus. 2022;21(2):230–238.
43 Jabbar HA, Muhamad SJ. Effectiveness of an Instructional Program on Gastric Carcinoma Patients Knowledge Undergoing Chemotherapy toward Self Care after Gastrectomy at Oncology Unit of AL-Haboby Teaching Hospital in AL-Naseria City. Indian Journal of Forensic Medicine and Toxicology. 2021;15(4):3156–3163.
44 Jaimalai W, Panuthai S, Chintanawat R, Juntasopeepun P. Effect of Medagogy-Based Medication Literacy Enhancement on Medication Adherence Among Older Persons with Physical Multimorbidity: Randomized Controlled Trial. Pacific Rim International Journal of Nursing Research. 2024;28(1):21–37.
45 Jangjoo M, Moeini F. The effect of Teach-back Method during discharge on the stress and anxiety of mothers of babies undergoing open heart surgery. Journal of Multidisciplinary Care. 2023;12(2):83–88.
46 Jia W, Yao L, Jian Z, . The Effects of WeChat-Based Teach-Back Health Education on Patients With Advanced Cancer Pain. Clinical Journal of Oncology Nursing. 2024;28(3):287–296.38830253
47 Kapoor A, Burns L, Foust JB, . Show Back: Developing and Testing of a Simulation-Based Assessment Method for Identifying Problems in Self-Management of Medications in Older Adults. Journal of Patient Safety. 2018;14(3):e36–e37.28448292
48 Kardine J. Effectiveness of 3D-printed Upper Extremity Device for Chronic Neurological Impairment. Archives of Physical Medicine and Rehabilitation. 2023;104(3):e24–e24.
49 Kennedy CM, Jolles DR. Providing effective asthma care at a pediatric patient-centered medical home. Journal of the American Association of Nurse Practitioners. 2021;33(2):167–173.
50 Kesanen J, Leino-Kilpi H, Lund T, . Spinal Stenosis Patients’ Visual and Verbal Description of the Comprehension of Their Surgery. Orthopaedic Nursing. 2019;38(4):253–261.31343630
51 khaja J, Premkumar B, Issac B, Gowri M. Effectiveness of Structured Teaching Programme on Knowledge and Practice Regarding Long Term Oxygen Therapy: A Pre-Experimental Study. International Journal of Nursing Education. 2018;10(4):59–63.
52 Khudhair SS, Ahmed SA. Effectiveness of an Educational Program on Type 2 Diabetic Patients’ Knowledge Regarding Risk Factors of Diabetic Foot. Pakistan Journal of Medical and Health Sciences. 2022;16(3):938–941.
53 Kim TK. CORR R International-Asia-Pacific: Closing the Loop-Focus Early and Often on Your Patients’ Postsurgical Rehabilitation Program. Clinical Orthopaedics and Related Research. 2020;478(10):2225–2227.32898042
54 Kindratt TB, Dallo FJ, Allicock M, . The influence of patient-provider communication on cancer screenings differs among racial and ethnic groups. Preventive Medicine Reports. 2020;18:101086.32309115
55 Konstantinos K. Self-Care Management of African American Men with Type 2 Diabetes. Self-Care Management Of African American Men With Type 2 Diabetes. 2018:1–1.
56 Kopelson K, de Peralta S, Pike NA. The 1-minute preceptor to improve diagnostic reasoning in a primary care nurse practitioner residency program. Journal of the American Association of Nurse Practitioners. 2024;04:04.
57 Kul UÇTu A, ÖZerdoĞAn N. EMZİRME EĞİTİMİNDE ÖĞRENDİĞİNİ ANLAT (TEACH-BACK) YÖNTEMİNİN KULLANIMI. Journal of Anatolia Nursing & Health Sciences / Anadolu Hemsirelik Ve Saglik Bilimleri Dergisi. 2020;23(1):162–168.
58 Kul Uctu A, Ozerdogan N. Effect of teach-back method on breastfeeding success: A single blind randomized controlled study. Health Care for Women International. 2023;44(3):314–327.35175908
59 Kumar R, Rehman S, Baloch GM, . Effectiveness of health education intervention on diabetes mellitus among the teachers working in public sector schools of Pakistan. BMC Endocrine Disorders. 2022;22(1):1–6.34983494
60 Kwaitana D, Van Breevoort D, Mnenula M, . Improving person-centred care for older persons with serious multimorbidity in LMICs. African journal of primary health care & family medicine. 2024;16(1):e1–e9.
61 Lampert A, Bruckner T, Haefeli WE, Seidling HM. Improving eye-drop administration skills of patients - A multicenter parallel-group cluster-randomized controlled trial. PLoS ONE [Electronic Resource]. 2019;14(2):e0212007.30789934
62 Lata K, Ajesh Kumar TK, Khakha DC, Deep R. Effectiveness of a Home Based Training Program on Caregivers Knowledge in Managing Aggressive Behavior of Patients With Mental Illness. Home Health Care Management & Practice. 2022;34(2):109–116.
63 Lay S, Moody N, Johnsen S, . Home Care Program Increases the Engagement in Patients With Heart Failure. Home Health Care Management & Practice. 2019;31(2):99–106.
64 Lee S, Khare MM, Olson HR, . The TEACH trial: Tailored education to assist label comprehension and health literacy. Research in Social & Administrative Pharmacy. 2018;14(9):839–845.29937110
65 Lemcke J, Starkey N, Lindsay D, Pain T. Patient recall and retention of lymphoedema-linked education knowledge following breast cancer surgery in Australia. Journal of Lymphoedema. 2022;17(1):24–28.
66 Li Y, Tang T, Chen X, . Evaluation of the effect of Teach-back health education model in preventing postoperative venous thromboembolism for gynecologic malignancies. Chinese Journal of Cancer Prevention and Treatment. 2023;30(8):490–496.
67 Lima MGR, Bahia JC, Oliveira FS, . Educational intervention improves knowledge and adherence to treatment amongst puerperal women with syphilis: randomized clinical trial. International Journal of STD and AIDS. 2023;34(13):969–977.37464586
68 Lin Q, Zhou H, Wu J, . Effect of Teach-back and Douyin platform short video health education in women receiving infertility treatment. Digital Health. 2023;9:20552076231203560.37771717
69 Lindblom S, Ytterberg C, Flink M, . The Use of Teach Back at Hospital Discharge to Support Self-Management of Prescribed Medication for Secondary Prevention after Stroke-Findings from A Feasibility Study. Healthcare. 2023;11(3):30.
70 Liu YB, Li YF, Liu L, Chen YL. Effectiveness of the teach-back method for improving the health literacy of senior citizens in nursing homes. Japan Journal of Nursing Science: JJNS. 2018;15(3):195–202.29152875
71 Lopez M, Ma C, Aavik L, Cortes TA. Implementing a quality improvement program to reduce falls and increase patient medication satisfaction in an academic medical center. Geriatric Nursing. 2023;49:207–211.36207230
72 Makiling M, Smart H. Patient-Centered Health Education Intervention to Empower Preventive Diabetic Foot Self-care. Advances in Skin & Wound Care. 2020;33(7):360–365.32544115
73 Maleki S, Glewis S, Fua T, . A randomised controlled trial of clinical pharmacy intervention versus standard care to improve medication adherence in outpatients with head and neck cancer receiving radiotherapy. Supportive Care in Cancer. 2022;30(5):4243–4253.35091845
74 Maricoto T, Correia-de-Sousa J, Taborda-Barata L. Inhaler technique education in elderly patients with asthma or COPD: impact on disease exacerbations-a protocol for a single-blinded randomised controlled trial. BMJ Open. 2019;9(1):e022685.
75 Marshall C. Teach-Back to Support Patient Understanding. Journal of Hospital Librarianship. 2022;22(1):61–64.
76 McDaniels BA, Hianik RS, Bellcross C, . The Impact of Genetic Counseling Educational Tools on Patients’ Knowledge of Molecular Testing Terminology. Journal of Cancer Education. 2020;35(5):864–870.31062281
77 McInerney S, Nanassy AD, Lavella H, . Implementation of an Abusive Head Trauma Prevention Program Through Interdisciplinary Collaboration: A Pilot Study. Journal of Trauma Nursing. 2020;27(5):276–282.32890241
78 McKerrocher PR, Hines CB. Antihypertensive Teach-Back to Reduce Delays, Cancellations, and Interventions in a Freestanding Gastroenterology Clinic. Gastroenterology Nursing. 2023;46(2):138–143.36727958
79 Milazi M, Douglas C, Bonner A. A bundled phosphate control intervention (4Ds) for adults with end-stage kidney disease receiving haemodialysis: A cluster randomized controlled trial. Journal of Advanced Nursing. 2021;77(3):1345–1356.33277736
80 Miller AN, Zraick R, Atmakuri S, . Characteristics of teach-back as practiced in a university health center, and its association with patient understanding, self-efficacy, and satisfaction. Patient Education and Counseling. 2021;104(11):2700–2705.34400041
81 Mohammadi F, Jahromi MS, Bijani M, . Investigating the effect of multimedia education in combination with teach-back method on quality of life and cardiac anxiety in patients with heart failure: a randomized clinical trial. BMC Cardiovascular Disorders. 2021;21(1):535.34772339
82 Molazem Z, Ebadi M, Khademian M, Zare R. Effects of an Educational Program for Prostate Cancer Prevention on knowledge and PSA Testing in Men Over 50 Years old in Community Areas of Shiraz in 2016. Asian Pacific Journal of Cancer Prevention: Apjcp. 2018;19(3):633–637.29580031
83 Morony S, Weir KR, Bell KJL, . A stepped wedge cluster randomised trial of nurse-delivered Teach-Back in a consumer telehealth service. PLoS ONE [Electronic Resource]. 2018;13(10):e0206473.30379942
84 Muscat DM, Ceprnja D, Hobbs K, . Development and evaluation of a health literacy training program for allied health professionals: A pre-post study assessing impact and implementation outcomes. Health promotion journal of Australia : official journal of Australian Association of Health Promotion Professionals. 2021;32:88–97.32320505
85 Muyiwa-Ojo I. Thirty-Day Readmissions Reduction Using Teach-Back Telephone Education. Thirty-Day Readmissions Reduction Using Teach-Back Telephone Education. 2018:1–1.
86 Naji AF, Abed RI. Effectiveness of an educational program on diabetic patients’ knowledge about preventive measures for retinopathy. Rawal Medical Journal. 2023;48(2):334–337.
87 Nazir SUR, Hassali MA, Saleem F, Haque N. Medication Management Program: Adherence, Disease-related Knowledge, Health-related Quality of Life, and Glycemic Control for Type 2 Diabetes Mellitus. Alternative Therapies in Health and Medicine. 2020;26(S2):4–10.
88 Newman JF, Kramer SI. Applying robust process improvement techniques to the voluntary inpatient psychiatry admission process. Journal of Clinical Outcomes Management. 2019;26(6):263–269.
89 Nguyen TS, Nguyen TLH, Van Pham TT, . Pharmacists’ training to improve inhaler technique of patients with COPD in Vietnam. International Journal of COPD. 2018;13:1863–1872.29928117
90 Nickles D, Dolansky M, Marek J, Burke K. Nursing students use of teach-back to improve patients’ knowledge and satisfaction: A quality improvement project. Journal of Professional Nursing. 2020;36(2):70–76.32204864
91 Nimri R, Audon P, Pinsker JE, Dassau E. Closing the Loop. Diabetes Technology & Therapeutics. 2018;20(S11):S41–S54.29437478
92 Nimri R, Murray N, Ochs A, . Closing the Loop. Diabetes Technology & Therapeutics. 2017;19(S1):S27–S41.
93 Orlandin L, Mazzo A, Meska MHG, . Low-fidelity simulation for patients and caregivers in the use of lubricants in clean intermittent catheterization. International Journal of Urological Nursing. 2018;12(1):9–15.
94 Orr TJ. Evaluation of Use of Teach-Back for Patient Education. Evaluation of Use of Teach-Back for Patient Education. 2018:1–1.
95 Oyesanya TO, LeCroy T, Sweatman M, . A Medication Management Intervention for Patients and Families with SCI and ABI. Western Journal of Nursing Research. 2020;42(12):1113–1128.32450769
96 Pandurangan H. Effectiveness of Structured Teaching Programme on Knowledge Regarding Prevention of Complications of Coronary Artery Disease among Patients with Cad. International Journal of Nursing Education. 2018;10(1):84–89.
97 Pei W, Yuxin Z, Peng Y, . Application of information health education combined with teach- back method in patients with posterior fossa tumors during perioperative period. Chinese Journal of Practical Nursing. 2023;39(30):2352–2358.
98 Perreault MM. Are We “Closing the Loop” on Meeting the Therapeutic Needs of Critically Ill Patients? Canadian Journal of Hospital Pharmacy / Journal Canadien de la Pharmacie Hospitalière. 2021;74(3):199–200.34248158
99 Peter D, Robinson P, Jordan M, . Reducing readmissions using teach-back: enhancing patient and family education. J Nurs Adm. 2015;45(1):35–42.25479173
100 Pinsker JE, Singh H, McElwee Malloy M, . A Virtual Training Program for the Tandem t:slim X2 Insulin Pump: Implementation and Outcomes. Diabetes Technology & Therapeutics. 2021;23(6):467–470.33439754
101 Porter B, John NA, Brenner R, . Urinary tract infection in multiple sclerosis: closing an audit loop by co-design and innovation. British Journal of Neuroscience Nursing. 2019;15(1):20–27.
102 Roopavathy GM, Panchaksharimath P. Impact of an education program on knowledge, metered-dose inhaler technique among asthma patients in a tertiary care hospital. National Journal of Physiology, Pharmacy and Pharmacology. 2023;13(10):2083–2088.
103 Rosdahl JA, Hein AM, Bosworth HB, . Randomized controlled trial of an education-based intervention to improve medication adherence: Design considerations in the medication adherence in glaucoma to improve care study. Clinical Trials. 2021;18(3):343–350.33487050
104 Ryan-Madonna M, Levin RF, Lauder B. Effectiveness of the Teach-Back Method for Improving Caregivers’ Confidence in Caring for Hospice Patients and Decreasing Hospitalizations. Journal of Hospice and Palliative Nursing. 2019;21(1):61–70.30608359
105 Sanchez-Nieto JM, Bernabeu-Mora R, Fernandez-Munoz I, . Effectiveness of individualized inhaler technique training on low adherence (LowAd) in ambulatory patients with COPD and asthma. npj Primary Care Respiratory Medicine. 2022;32(1):1.
106 Seely KD, Higgs JA, Butts L, . The “teach-back” method improves surgical informed consent and shared decision-making: a proof of concept study. Patient Safety in Surgery [Electronic Resource]. 2022;16(1):33.36307856
107 Shichijo Y, Ko F. Patient Safety in Transitions of Care: Addressing Discharge Communication Gaps and the Potential of the Teach-Back Method. Journal of Clinical Outcomes Management. 2023;30(3):58–61.
108 Shigli K, Nayak SS, Kusurkar RA, Chari S. Use “LATCHeS” to communicate with elderly patients. Vol. 40. Malden, Massachusetts: Wiley-Blackwell; 2020:390–392.
109 Zhang S, Ouyang H, Jingduan HAN. Application of positive psychological suggestion therapy combined with Teach-back health education in the clinical care of patients with psoriasis. Chinese Evidence-based Nursing. 2024;10(7):1215–1219.
110 Stuart TA, Stutzman SE, Hicks AD, Olson DM. Patient Education: A Comparison of Teaching Strategies for Patients With Brain Neoplasms. Clinical Journal of Oncology Nursing. 2019;23(5):E81–E86.31538982
111 Subramanian SC, Porkodi A, Akila P. Effectiveness of nurse-led intervention on self-management, self-efficacy and blood glucose level among patients with Type 2 diabetes mellitus. Journal of Complementary & Integrative Medicine. 2020;17(3):23.
112 Subramanya AP, Prabhuji MLV. Comparative evaluation of efficacy and patient-reported outcome measures of oral hygiene instruction methods for calibrated interdental brush. International Journal of Dental Hygiene. 2021;19(3):287–294.34101341
113 Thakur T, Frey M, Chewning B. Student pharmacist opioid consultations with standardized limited English proficiency patients: A pre-post educational intervention study. Currents in Pharmacy Teaching & Learning. 2021;13(2):146–151.33454071
114 Thomas L. Reducing Congestive Heart Failure Hospital Readmissions Through Discharge Planning. Reducing Congestive Heart Failure Hospital Readmissions Through Discharge Planning. 2018:1–1.
115 Thomas S, Mathai S, Shenai S, Varghese SM. Effectiveness of Structured Teaching Programme on Knowledge Regarding Hypoglycemia and its Management among Diabetic Patients. International Journal of Nursing Education. 2019;11(1):140–143.
116 Thomas TLJ, Jacob S, Varghese L, . Standardizing the Teach-Back Method for Post Procedure Discharge Instructions to Improve Patient Satisfaction. Journal of Perianesthesia Nursing. 2021;36(4):e7–e7.
117 Trela KC, Zajac P, Zhu M, Press VG. Health literacy and type of education intervention predicting post-education metered-dose inhaler misuse. Respiratory Medicine. 2022;200:106930.35870435
118 Ulrich L, Welty M, Henderson A, Allen E. Quality improvement approach to increasing respiratory therapist driven teach back style asthma education. Journal of Asthma. 2022;59(4):823–828.
119 Uzun LN, Hancer Tok H. Perineal care incontinence training for caregivers: randomised controlled trial. BMJ supportive & palliative care. 2023;31:31.
120 van der Giessen J, Fransen MP, Spreeuwenberg P, . Communication about breast cancer genetic counseling with patients with limited health literacy or a migrant background: evaluation of a training program for healthcare professionals. Journal of Community Genetics. 2021;12(1):91–99.33319336
121 Vazquez-Gonzalez N, Leiva-Fernandez J, Cotta-Luque VM, . Effectiveness of an educational intervention about inhalation technique in healthcare professionals in primary care: a cluster randomized trial. Frontiers in Pharmacology. 2023;14:1266095.37915412
122 Voelliger CM, VanderZwan KJ, Coyne EP, . Education of Self-Radial Pulse Palpation and Atrial Fibrillation Signs and Symptoms. Journal of Community Health Nursing. 2021;38(3):193–199.34148433
123 Wang F, Feng WM, Zhu M, . A study on the effect of using the video teach-back method in continuous nursing care of stroke patients. Frontiers in Public Health. 2024;12:1275447.38532972
124 Wang J, Hu H, Sun J, . The effectiveness of health education based on the 5Ts for teach-back on oral nutritional supplements compliance of post-discharge patients after surgery for gastric cancer: a randomized controlled trial. Supportive Care in Cancer. 2023;31(3):157.36773116
125 Wang P, Zhang Q, Li GP, . Effectiveness of a Teach-Back Education Program on Perioperative Pain in Patients With Lung Cancer: An Intervention Study Using Behavior Change Wheel. Pain Management Nursing. 2024;11:11.
126 White M, Garbez R, Carroll M, . Is “teach-back” associated with knowledge retention and hospital readmission in hospitalized heart failure patients? J Cardiovasc Nurs. 2013;28(2):137–46.22580624
127 Xia F, Wang G. Influence of teach-back strategy on hemodialysis related knowledge level, self-efficacy and self-management in patients receiving maintenance hemodialysis. Scientific Reports. 2024;14(1):4010.38369580
128 Yilmaz Z, Bulut K. Necessity and impact of patient education driven by pharmacist on the knowledge level of diabetic patients. Journal of Research in Pharmacy. 2023;27(5):1911–1923.
129 Yousif K, Ei Maki M, Babikir RK, Abuaisha H. The effect of an educational intervention on awareness of various aspects of pulmonary tuberculosis in patients with the disease. Eastern Mediterranean Health Journal. 2021;27(3):287–292.33788218
130 Zimenkovsky A, Nastyukha Y, Boretska O, . Perception of information about drugs by a patient as an aspect of pharmaceutical care on the example of non-steroidal anti-inflammatory drugs. Pharmacia. 2018;65(1):18–33.
131 김남희, 태영숙. The Development and Evaluation of Navigation Program for Caregivers of Stroke Patients Admitted to a Rehabilitation Centers: A Pilot Study. Korean Journal of Adult Nursing. 2018;30(3):277–289.
132 张玉梅, 王林, 陈爱民, . 强化回授法在精神病院长期住院患者 跌倒预防健康教育中应 用. Nursing of Integrated Traditional Chinese & Western Medicine. 2018;4(10):135–138.
133 杨建梅, 杨红娟, 陈云霞, 俞 冲. 以PBL为启发式理念实施 Teach-back健康教育 对肝硬化失 代偿期病人自我管理的影响. Chinese General Practice Nursing. 2023;21(28):3959–3962.
134 欧瑞肖, 金瑞华, 淮盼盼, . 基于反馈理论的 Teach⁃back 教学模式 对护生核心能力的影响. Chinese Nursing Research. 2022;36(5):927–930.
135 潘卫宇, 张俊娟, 李伟玲, . 创新型 Teach-back工具包改善全膝关节置换术 病人功能锻 炼依从性及康复效果的研究. Chinese Nursing Research. 2022;36(23):4243–4247.
136 王莹. 情绪ABC理论结合Teach-back 健康教育在四肢骨折手 术病人中的应用. Chinese Nursing Research. 2021;35(24):4465–4470.

## ANALYTIC FRAMEWORK

Analytic framework informed by Street et al. 2009 shows patients in clinical settings text connected with a dashed line to a box containing teach-back communication for patient education. Directional arrows connect the implementation strategies box to the teach-back box and to implementation outcomes (ie, adoption, fidelity, confidence, conviction) box (KQ2). The teach-back box is also connected with a directional arrow to proximal patient outcomes (ie, knowledge/skills, satisfaction, patient health literacy) as well as intermediate patient outcomes (ie, access to care, adherence, self-efficacy, engagement) (KQ1). These boxes are connected with a dashed line to distal outcomes (ie, survival, emotional well-being, functional status, healthcare utilization).

## RISK OF BIAS ASSESSMENTS

### RANDOMIZED CONTROLLED TRIALS (ROB-2)

Author, Year | Randomization | Deviations From Intended Interventions | Missing Outcome Data | Measurement of the Outcome | Selection of the Reported Result | Overall Bias
Berthelsen, 2020^47^ | Low | Low | Low | Low | Low | Low
Cetindemir, 2024^48^ | Low | Some Concerns | Low | Low | Some Concerns | Some Concerns
Cetindemir, 2024^48^ | Low | Likely unblinded due to behavioral nature of intervention; no evidence to suggest per protocol or as-treated analyses | Low | Low | Authors did not report and discuss effect size, it is possible that this was an intentional omission | Some Concerns
Ghorbani, 2021^49^ | Low | Some Concerns | Low | Some Concerns | Some Concerns | Some Concerns
Ghorbani, 2021^49^ | Low | No blinding; no discussion contamination or fidelity; not clear if ITT versus PP analysis | Low | Self-reported outcomes without blinding | Analysis description unclear | Some Concerns
Goni, 2024^25^ | Some Concerns | Low | High | High | Low | High
Goni, 2024^25^ | Participants not randomized; allocation not described | Low | handling loss to follow-up | likely data collection by interventionist | Low | High
Griffey, 2015^50^ | High | Low | High | High | Some Concerns | High
Griffey, 2015^50^ | Allocation concealment concerns; baseline imbalances | Low | High rates of follow-up with timing of discharge likely main reason | Outcomes assessment completed by unblinded interventionist | Concordance with the medical record described but not clearly reported | High
Joseph 2024^51^ | Some Concerns | Some Concerns | High | Some Concerns | Low | High
Joseph 2024^51^ | Randomization not described | Unblinded; inadequate consideration of cross-over (45% of the control arm received the after-visit instructions) | Missing detail on original N enrolled and dropout rate | Outcome assessors likely unblinded | Low | High
Mesbahi, 2020^26^ | Some Concerns | Low | Low | Low | Low | Some Concerns
Mesbahi, 2020^26^ | Allocation concealment unclear | Low | Low | Low | Low | Some Concerns
Nas, 2021^52^ | Low | Low | Low | Low | Low | Low
Oh, 2023^23^ | Low | Some Concerns | Low | Some Concerns | Some Concerns | Some Concerns
Oh, 2023^23^ | Low | No blinding; not clear if ITT versus PP analysis | Low | Mostly self-report outcomes from unblinded participants | Lack of clarity on what control variables were used in analysis | Some Concerns
Press 2020^53^ | Some Concerns | Low | Low | Low | Low | Low
Press 2020^53^ | Imbalance of key baseline variable | Low | Low | Low | Low | Low
Rahmani 2020^54^ | Some Concerns | Some Concerns | Low | High | High | High
Rahmani 2020^54^ | No description randomization process | Not able to blind; not clear if ITT versus PP analysis | Low | Measure appears to be used differently from how it was intended | Numerous analyses; no correction for multiple comparisons | High
Saadatian, 2022^55^ | High | Some Concerns | Some Concerns | Some Concerns | Some Concerns | High
Saadatian, 2022^55^ | Imbalance of key baseline variables; limited description randomization process and allocation concealment | Suspect data collected by unblinded interventionist; fidelity to planned intervention concerns | Final N analyzed not reported | Some Concerns | There were only 2 validated surveys used | High
Satehi, 2021^56^ | Some Concerns | Some Concerns | Some Concerns | Low | Some Concerns | Some Concerns
Satehi, 2021^56^ | No description randomization process | Single-blinded study; No information about deviations from intended interventions | No information on retention or loss to follow-up | Low | Multiple analyses of similar outcomes | Some Concerns
Shen, 2013^57^ | Low | Some Concerns | Low | Some Concerns | Some Concerns | Some Concerns
Shen, 2013^57^ | Low | Blinding of patients not possible; not clear if ITT versus PP analysis | Low | Questionable outcome measure choice and unclear assessment blinding | Multiple measurements and scales used to assess 2 outcomes | Some Concerns
Teshnizi, 2024^58^ | Some Concerns | Low | Low | Some Concerns | Some Concerns | Some Concerns
Teshnizi, 2024^58^ | Small n with some baseline difference between groups | Low | Low | Patient self-reported outcomes likely influenced by awareness of educational intervention; unblinded analysis | Concerns about presented data | Some Concerns
Tran, 2019^59^ | Low | Low | Some Concerns | Low | Some Concerns | Some Concerns
Tran, 2019^59^ | Low | Low | High drop-out rates | Low | Results reported in multiple ways without clear rationale; data conflict between abstract and narrative | Some Concerns
Berthelsen, 2020^47^ | Low | Low | Low | Low | Low | Low
Cetindemir, 2024^48^ | Low | Some Concerns | Low | Low | Some Concerns | Some Concerns
Cetindemir, 2024^48^ | Low | Likely unblinded due to behavioral nature of intervention; no evidence to suggest per protocol or as-treated analyses | Low | Low | Authors did not report and discuss effect size, it is possible that this was an intentional omission | Some Concerns
Ghorbani, 2021^49^ | Low | Some Concerns | Low | Some Concerns | Some Concerns | Some Concerns
Ghorbani, 2021^49^ | Low | No blinding; no discussion contamination or fidelity; not clear if ITT versus PP analysis | Low | Self-reported outcomes without blinding | Analysis description unclear | Some Concerns
Goni, 2024^25^ | Some Concerns | Low | High | High | Low | High
Goni, 2024^25^ | Participants not randomized; allocation not described | Low | handling loss to follow-up | likely data collection by interventionist | Low | High
Griffey, 2015^50^ | High | Low | High | High | Some Concerns | High
Griffey, 2015^50^ | Allocation concealment concerns; baseline imbalances | Low | High rates of follow-up with timing of discharge likely main reason | Outcomes assessment completed by unblinded interventionist | Concordance with the medical record described but not clearly reported | High
Joseph 2024^51^ | Some Concerns | Some Concerns | High | Some Concerns | Low | High
Joseph 2024^51^ | Randomization not described | Unblinded; inadequate consideration of cross-over (45% of the control arm received the after-visit instructions) | Missing detail on original N enrolled and dropout rate | Outcome assessors likely unblinded | Low | High
Mesbahi, 2020^26^ | Some Concerns | Low | Low | Low | Low | Some Concerns
Mesbahi, 2020^26^ | Allocation concealment unclear | Low | Low | Low | Low | Some Concerns
Nas, 2021^52^ | Low | Low | Low | Low | Low | Low
Oh, 2023^23^ | Low | Some Concerns | Low | Some Concerns | Some Concerns | Some Concerns
Oh, 2023^23^ | Low | No blinding; not clear if ITT versus PP analysis | Low | Mostly self-report outcomes from unblinded participants | Lack of clarity on what control variables were used in analysis | Some Concerns
Press 2020^53^ | Some Concerns | Low | Low | Low | Low | Low
Press 2020^53^ | Imbalance of key baseline variable | Low | Low | Low | Low | Low
Rahmani 2020^54^ | Some Concerns | Some Concerns | Low | High | High | High
Rahmani 2020^54^ | No description randomization process | Not able to blind; not clear if ITT versus PP analysis | Low | Measure appears to be used differently from how it was intended | Numerous analyses; no correction for multiple comparisons | High
Saadatian, 2022^55^ | High | Some Concerns | Some Concerns | Some Concerns | Some Concerns | High
Saadatian, 2022^55^ | Imbalance of key baseline variables; limited description randomization process and allocation concealment | Suspect data collected by unblinded interventionist; fidelity to planned intervention concerns | Final N analyzed not reported | Some Concerns | There were only 2 validated surveys used | High
Satehi, 2021^56^ | Some Concerns | Some Concerns | Some Concerns | Low | Some Concerns | Some Concerns
Satehi, 2021^56^ | No description randomization process | Single-blinded study; No information about deviations from intended interventions | No information on retention or loss to follow-up | Low | Multiple analyses of similar outcomes | Some Concerns
Shen, 2013^57^ | Low | Some Concerns | Low | Some Concerns | Some Concerns | Some Concerns
Shen, 2013^57^ | Low | Blinding of patients not possible; not clear if ITT versus PP analysis | Low | Questionable outcome measure choice and unclear assessment blinding | Multiple measurements and scales used to assess 2 outcomes | Some Concerns
Teshnizi, 2024^58^ | Some Concerns | Low | Low | Some Concerns | Some Concerns | Some Concerns
Teshnizi, 2024^58^ | Small n with some baseline difference between groups | Low | Low | Patient self-reported outcomes likely influenced by awareness of educational intervention; unblinded analysis | Concerns about presented data | Some Concerns
Tran, 2019^59^ | Low | Low | Some Concerns | Low | Some Concerns | Some Concerns
Tran, 2019^59^ | Low | Low | High drop-out rates | Low | Results reported in multiple ways without clear rationale; data conflict between abstract and narrative | Some Concerns
Berthelsen, 2020^47^ | Low | Low | Low | Low | Low | Low
Cetindemir, 2024^48^ | Low | Some Concerns | Low | Low | Some Concerns | Some Concerns
Cetindemir, 2024^48^ | Low | Likely unblinded due to behavioral nature of intervention; no evidence to suggest per protocol or as-treated analyses | Low | Low | Authors did not report and discuss effect size, it is possible that this was an intentional omission | Some Concerns
Ghorbani, 2021^49^ | Low | Some Concerns | Low | Some Concerns | Some Concerns | Some Concerns
Ghorbani, 2021^49^ | Low | No blinding; no discussion contamination or fidelity; not clear if ITT versus PP analysis | Low | Self-reported outcomes without blinding | Analysis description unclear | Some Concerns
Goni, 2024^25^ | Some Concerns | Low | High | High | Low | High
Goni, 2024^25^ | Participants not randomized; allocation not described | Low | handling loss to follow-up | likely data collection by interventionist | Low | High
Griffey, 2015^50^ | High | Low | High | High | Some Concerns | High
Griffey, 2015^50^ | Allocation concealment concerns; baseline imbalances | Low | High rates of follow-up with timing of discharge likely main reason | Outcomes assessment completed by unblinded interventionist | Concordance with the medical record described but not clearly reported | High
Joseph 2024^51^ | Some Concerns | Some Concerns | High | Some Concerns | Low | High
Joseph 2024^51^ | Randomization not described | Unblinded; inadequate consideration of cross-over (45% of the control arm received the after-visit instructions) | Missing detail on original N enrolled and dropout rate | Outcome assessors likely unblinded | Low | High
Mesbahi, 2020^26^ | Some Concerns | Low | Low | Low | Low | Some Concerns
Mesbahi, 2020^26^ | Allocation concealment unclear | Low | Low | Low | Low | Some Concerns
Nas, 2021^52^ | Low | Low | Low | Low | Low | Low
Oh, 2023^23^ | Low | Some Concerns | Low | Some Concerns | Some Concerns | Some Concerns
Oh, 2023^23^ | Low | No blinding; not clear if ITT versus PP analysis | Low | Mostly self-report outcomes from unblinded participants | Lack of clarity on what control variables were used in analysis | Some Concerns
Press 2020^53^ | Some Concerns | Low | Low | Low | Low | Low
Press 2020^53^ | Imbalance of key baseline variable | Low | Low | Low | Low | Low
Rahmani 2020^54^ | Some Concerns | Some Concerns | Low | High | High | High
Rahmani 2020^54^ | No description randomization process | Not able to blind; not clear if ITT versus PP analysis | Low | Measure appears to be used differently from how it was intended | Numerous analyses; no correction for multiple comparisons | High
Saadatian, 2022^55^ | High | Some Concerns | Some Concerns | Some Concerns | Some Concerns | High
Saadatian, 2022^55^ | Imbalance of key baseline variables; limited description randomization process and allocation concealment | Suspect data collected by unblinded interventionist; fidelity to planned intervention concerns | Final N analyzed not reported | Some Concerns | There were only 2 validated surveys used | High
Satehi, 2021^56^ | Some Concerns | Some Concerns | Some Concerns | Low | Some Concerns | Some Concerns
Satehi, 2021^56^ | No description randomization process | Single-blinded study; No information about deviations from intended interventions | No information on retention or loss to follow-up | Low | Multiple analyses of similar outcomes | Some Concerns
Shen, 2013^57^ | Low | Some Concerns | Low | Some Concerns | Some Concerns | Some Concerns
Shen, 2013^57^ | Low | Blinding of patients not possible; not clear if ITT versus PP analysis | Low | Questionable outcome measure choice and unclear assessment blinding | Multiple measurements and scales used to assess 2 outcomes | Some Concerns
Teshnizi, 2024^58^ | Some Concerns | Low | Low | Some Concerns | Some Concerns | Some Concerns
Teshnizi, 2024^58^ | Small n with some baseline difference between groups | Low | Low | Patient self-reported outcomes likely influenced by awareness of educational intervention; unblinded analysis | Concerns about presented data | Some Concerns
Tran, 2019^59^ | Low | Low | Some Concerns | Low | Some Concerns | Some Concerns
Tran, 2019^59^ | Low | Low | High drop-out rates | Low | Results reported in multiple ways without clear rationale; data conflict between abstract and narrative | Some Concerns
Berthelsen, 2020^47^ | Low | Low | Low | Low | Low | Low
Cetindemir, 2024^48^ | Low | Some Concerns | Low | Low | Some Concerns | Some Concerns
Cetindemir, 2024^48^ | Low | Likely unblinded due to behavioral nature of intervention; no evidence to suggest per protocol or as-treated analyses | Low | Low | Authors did not report and discuss effect size, it is possible that this was an intentional omission | Some Concerns
Ghorbani, 2021^49^ | Low | Some Concerns | Low | Some Concerns | Some Concerns | Some Concerns
Ghorbani, 2021^49^ | Low | No blinding; discussion contamination or fidelity; not clear if ITT versus PP analysis | Low | Self-reported outcomes without blinding | Analysis description unclear | Some Concerns
Goni, 2024^25^ | Some Concerns | Low | High | High | Low | High
Goni, 2024^25^ | Participants not randomized; allocation not described | Low | handling loss to follow-up | likely data collection by interventionist | Low | High
Griffey, 2015^50^ | High | Low | High | High | Some Concerns | High
Griffey, 2015^50^ | Allocation concealment concerns; baseline imbalances | Low | High rates of follow-up with timing of discharge likely main reason | Outcomes assessment completed by unblinded interventionist | Concordance with the medical record described but not clearly reported | High
Joseph 2024^51^ | Some Concerns | Some Concerns | High | Some Concerns | Low | High
Joseph 2024^51^ | Randomization not described | Unblinded; inadequate consideration of cross-over (45% of the control arm received the after-visit instructions) | Missing detail on original N enrolled and dropout rate | Outcome assessors likely unblinded | Low | High
Mesbahi, 2020^26^ | Some Concerns | Low | Low | Low | Low | Some Concerns
Mesbahi, 2020^26^ | Allocation concealment unclear | Low | Low | Low | Low | Some Concerns
Nas, 2021^52^ | Low | Low | Low | Low | Low | Low
Oh, 2023^23^ | Low | Some Concerns | Low | Some Concerns | Some Concerns | Some Concerns
Oh, 2023^23^ | Low | No blinding; not clear if ITT versus PP analysis | Low | Mostly self-report outcomes from unblinded participants | Lack of clarity on what control variables were used in analysis | Some Concerns
Press 2020^53^ | Some Concerns | Low | Low | Low | Low | Low
Press 2020^53^ | Imbalance of key baseline variable | Low | Low | Low | Low | Low
Rahmani 2020^54^ | Some Concerns | Some Concerns | Low | High | High | High
Rahmani 2020^54^ | No description randomization process | Not able to blind; not clear if ITT versus PP analysis | Low | Measure appears to be used differently from how it was intended | Numerous analyses; no correction for multiple comparisons | High
Saadatian, 2022^55^ | High | Some Concerns | Some Concerns | Some Concerns | Some Concerns | High
Saadatian, 2022^55^ | Imbalance of key baseline variables; limited description randomization process and allocation concealment | Suspect data collected by unblinded interventionist; fidelity to planned intervention concerns | Final N analyzed not reported | Some Concerns | There were only 2 validated surveys used | High
Satehi, 2021^56^ | Some Concerns | Some Concerns | Some Concerns | Low | Some Concerns | Some Concerns
Satehi, 2021^56^ | No description randomization process | Single-blinded study; No information about deviations from intended interventions | No information on retention or loss to follow-up | Low | Multiple analyses of similar outcomes | Some Concerns
Shen, 2013^57^ | Low | Some Concerns | Low | Some Concerns | Some Concerns | Some Concerns
Shen, 2013^57^ | Low | Blinding of patients not possible; not clear if ITT versus PP analysis | Low | Questionable outcome measure choice and unclear assessment blinding | Multiple measurements and scales used to assess 2 outcomes | Some Concerns
Teshnizi, 2024^58^ | Some Concerns | Low | Low | Some Concerns | Some Concerns | Some Concerns
Teshnizi, 2024^58^ | Small n with some baseline difference between groups | Low | Low | Patient self-reported outcomes likely influenced by awareness of educational intervention; unblinded analysis | Concerns about presented data | Some Concerns
Tran, 2019^59^ | Low | Low | Some Concerns | Low | Some Concerns | Some Concerns
Tran, 2019^59^ | Low | Low | High drop-out rates | Low | Results reported in multiple ways without clear rationale; data conflict between abstract and narrative | Some Concerns

## STUDY CHARACTERISTICS

### KQ1

Author Name, Year; Country; Sample Size | Study Design; Health Condition Study Focuses On; Setting; Brief Intervention Description | Population; Mean Age (SD); N, % Women | Comparator; Outcomes Reported; Timing Outcomes Measured
Berthelsen, 2020^47^; Sweden; 50 | Randomized controlled trial; Post-operative care for patients undergoing upper abdominal or endocrinological surgery; Outpatient multi-disciplinary clinic; Participant received verbal information regarding (a) early mobilization/ambulation, (b) breathing exercises, (c) post-discharge physical activity and restrictions and asked to retell what they had heard | Patients scheduled to undergo major open abdominal surgery at Sahlgrenska University Hospital; NR; 21, 43.8% | Received same information; were allowed to ask questions according to usual practice; Knowledge; Two to 4 days after attending the preoperative clinic
Çetindemir, 2024^48^; Turkey; 100 | Randomized controlled trial; Breastfeeding; Outpatient; Participants received education and counseling based on the content of a Breastfeeding Education Guide and were asked to reiterate what they were taught | Patients who: are 18 years of age or older, have basic literacy skills, have a full-term and healthy delivery, have a healthy newborn, and anomalies in the newborn that would hinder breastfeeding; 26.23 (4.77); 44, 100% | Standard education/usual care; Self-efficacy; Adherence; 24 hours postpartum; 1 month postpartum
Ghorbani, 2021^49^; Iran (Islamic Republic of); 123 | Randomized controlled trial; Adherence to a therapeutic regimen in patients after CABGS; Inpatient; Teach-back intervention: Researcher delivered information and “corrected the patient’s misinformation” | Patients were: age 18-60 years old, had an Android phone, able to receive phone calls after discharge, not on any psychotropic drugs, could understand and speak Persian, and free from any hearing and speech disorders.; NR; 18, 48.6% | Usual care. There was a second intervention using gamification; Adherence; After 30 days
Goni, 2024^25^; Australia; 29 | Randomized controlled trial; Myocardial infarcion; Outpatient; Pharmacist interviewed participants regarding non-adherence and comprehension of medication plan and provided individualized information using the teach-back technique | Patients or carer of a patient, admitted primarily due to an MI diagnosis; at least 18 years old; able to provide informed consent for participation; and the discharge destination was home where the patient or their carer managed their medicines; NR; NR | Usual care; Knowledge; Adherence; 1 week; 12 weeks
Griffey, 2015^50^; United States; 408 | Randomized controlled trial; Emergency department discharge; Outpatient; For patients in the intervention group, a medical student research assistant accompanied the patient’s nurse in the patient’s room while the nurse gave discharge instructions. After the nurse gave the instructions, the research assistant asked the patient to repeat back their understanding in their own words. and the nurse would correct misunderstandings. | Patients aged 18 and older who are discharged from the emergency department and who scored 6 or less on the Rapid Estimate of Adult Literacy in Medicine-Revised measure for health literacy.; NR; NR | Standard discharge; Knowledge; Patient satsifaction; Immediately post-intervention
Joseph, 2024^51^; United States; 120 | Randomized controlled trial; Rheumatic diseases; Outpatient; Standardized after visit instructions group (sAVI): participants received after visit instructions that were written using a standardized template; sAVI + teach-back group: participants received the standardized (templated) after visit instructions and the patient then repeated back what changes and future management had been decided on during the visit. | The inclusion criteria were patients who were older than 18 years of age and patients seen in the RUMCRC.; NR; NR | Usual care; Knowledge; Patient satisfaction; Provider-reported feasibility; Provider satisfaction; Day 1 of clinic visit; 7 – 14 days after clinic visit
Mesbahi, 2020^26^; Iran; 80 | Randomized controlled trial; Class II-IV heart failure.; Inpatient; Four sessions of teach-back on self-care (content included information about diet, medication regimen, physical activity, weight control, fluid intake, warning signs of exacerbation, sleep, rest, methods of muscle relaxation) in which information was given and patients were asked to “were asked to recite the instructed materials in their language.” | Moderate and severe heart failure based on NYHA Classification (Classes II, III, and IV), having no mental disorders, the ability to communicate and cooperate, being over 30 years, having a minimum literacy, not attending a face-to-face training program, having no chronic diseases (eg, thyroid and renal and hepatic failure), having no movement restriction, and residing in the city of Zahedan.; 64.05 (12.97); 23, 57.5% | Active Control. The control group received “conventional training” during education sessions instead of teach-back. Both groups received four 30-60 minute education sessions and a booklet continaing training session materials.; Adherence; 3 months post-discharge
Nas, 2021^52^; Turkey; 70 | Randomized controlled trial; Diabetes; Outpatient; Participants received information about diabetes and “were asked to explain new information in their own words.” | Type 2 DM patients who were over 18 years old, who did not have any barriers in understanding and speaking Turkish, and who started insulin treatment for the first time were included in the study.; 54.2 (8.7); 23, 74.2% | Usual diabetes education (without teach-back); Knowledge; Baseline; 1 week; 1 month
Oh, 2023^23^; Korea (Republic of); 100 | Randomized controlled trial; Heart-failure; Inpatient; Participants received a 15-minute educational session (HEART program) including 7 heart failure related topics (definition of heart failure, medication, symptom management, weight management, dietary management, physical activity, and other precautions). After the session, participants were asked 15 pre-structured teach-back questions. | Age 19 years or older, heart failure diagnosis, EF < 50%; 59.6 (12.4); NR | Usual care -15 minute face-to-face discharge education on same topics but without teach-back method; no written materials; Self-care efficacy; Adherence; 1 week post discharge; 1 month post discharge
Press, 2020^53^; United States; 121 | Randomized controlled trial; Inhaler use; Inpatient; Virtual teach-back group: (a) pre-demonstration self-assessment questions, (b) narrated video demonstration of inhaler technique, (c) post-demonstration self-assessment questions – all delivered on a tablet device; In-person teach-back group: Up to 3 rounds of inhaler education technique followed by comprehension assessments (“teach-back”). | Older than 18 years old, hospitalized on an inpatient medical service, had a physician diagnosis of asthma or COPD, expected to be discharged home on metered dose inhaler by their inpatient physician also passed a vision screening.; NR; NR | Virtual asynchronous self-assessment questions; Knowledge; Immediately post intervention; 30-day follow-up
Rahmani, 2020^54^; Iran (Islamic Republic of); 70 | Randomized controlled trial; Heart failure; Inpatient; Participants received information on heart failure (symptoms, symptom management, salt intake, fluid intake, exercise, medication, daily weights, warning signs) after which “the patient was asked to give feedback to the nurse on what he/she had learned.” | Advanced heart failure, defined as reduced systolic function (EF of 40%); age range of 45-85 years; at least 6 months have passed since the diagnosis of heart failure; absence of cognitive problems; be literate and native Persian-speaking.; 66.7 (18.9); NR | Routine care; Self-efficacy; Immediately after intervention; 3 months post discharge
Saadatian, 2022^55^; Iran; 100 | Randomized controlled trial; Coronary Artery Disease; Inpatient; Participants received 3 sessions (session topics: illness perception, self-efficacy, and overview) each of which was followed by being asked to “repeat the instructed concept or topic in their own words.” | Participants were required to have a definite diagnosis of coronary artery disease (CAD) without a history of myocardial infarction, be between the ages of 18 and 70, and have an ejection fraction (EF) greater than 40%, be able to speak and understand Persian, have at least minimum literacy, the ability to communicate effectively, no prior attendance in similar face-to-face training programs, and the absence of mental disorders or severe chronic diseases, such as thyroid conditions, cancer, obstructive lung disease, asthma, or liver and kidney damage; 50.22 (10.03); NR | Usual care (described as “routine training”); Self-efficacy; Pre-intervention; One month post intervention
Satehi, 2021^56^; Iran (Islamic Republic of); 90 | Randomized controlled trial; Diabetic foot ulcer; Inpatient; Single session of a one-on-one educational program about diabetic foot ulcer self-care; at the end of the session, participants were asked to “retell the material in their own words as they understood it” at the end of the session. | The patient eligibility criteria include individuals aged 20 to 80 years with a physician-diagnosed history of diabetes based on medical records. The patient must have a history of diabetic foot ulcers or risk factors such as sensory or motor neuropathy. The patient should have an active foot ulcer that does not require amputation, as determined by the physician, and must not have had any prior amputations. Additionally, the patient should not be receiving immunosuppressive drug therapy (eg, corticosteroids). The patient or a close family member must be able to read and write. The individual should have no formal education in medical sciences and no previous training in ulcer care. The patient must be in appropriate mental and psychological health, capable of receiving phone calls, and able to use a mobile phone to watch educational videos.; 55.56 (11.23); NA | Control/usual care; Multimedia intervention; Self-efficacy; Two weeks post intervention
Shen, 2023^57^; China; 116 | Randomized controlled trial; Ophthalmic conditions; Outpatient; Distributed preoperative education manuals (including information such as surgical methods and medications, and skills/technique descriptions such as techniques for coughing/sneezing during surgery) after which participants were asked to review the content verbally with the interventionist or demonstrate a described technique. | American Society of Anesthesiologists grade: I to II; at least 60 years old; Clear consciousness, barrier-free language communication, and basic listening, speaking, reading, and writing skills; Receiving ophthalmic local anesthesia surgery for the first time; Patients who were volunteered to participate in the group. “; 67.10 (5.02); NR | Usual care; Knowledge; Adherence; Pre-intervention; During the surgery; Post-intervention
Teshnizi, 2024^58^; Iran; 90 | Randomized controlled trial; Type 2 Diabetes; Outpatient; Educational booklet with information about diabetes medical care and lifestyle management (from American Diabetes Association 2019 guidelines) provided to participants face-to-face after which each participant was asked to express their understanding of the material. | Less than 30 years of age, having had diabetes diagnosis for more than a year, lack of any mental illness that interferes with the intervention, non-participation in similar educational programs, ability to understand conversation in the Persian language, and lack of difficulty in communication (such as loss of hearing and vision).; 50.46 (13.17); 24, 53.3% | Usual care; Adherence; 1 week; 40 days
Tran, 2019^59^; Australia; 70 | Randomized controlled trial; Chronic hepatitis B; Outpatient; Education session regarding 4 domains of chronic hepatitis B (transmission, natural history, epidemiology and prevention, and clinical management) including The Hepatitis B Story (a low health literacy educational resource) with teach-back questions to confirm understanding after each concept was presented. | Adults aged 18 years or older, living with CHB and compensated liver disease, were recruited from the outpatient liver clinic at a Melbourne tertiary hospital. Eligible participants were chronically infected, defined as HBsAg-positive for more than 6 months. Due to logistical reasons, only English-speaking patients, as determined by self-assessment, were included in the study. | Usual care via routine, standard appointment with gastroenterologist.; Knowledge; Immediately post-intervention; 1 month follow-up

### KQ2

Author, Year; Country; Sample Size (unit) | Study Design; Setting; Staff Description; Health Condition/Context | Implementation Strategies | Comparator; Implementation Outcomes; Timing Outcomes Measured
Burmeister, 2022^35^; United States; 81 (discharges) | Single site, QI project, pre-post; 24-bed surgical inpatient unit; Nurses; Discharge-specific patient education upon admission and continued during stay | Tailor, iterate, and adapt to context; Train site staff and clinicians; Provide interactive assistance and site support; Support clinician practice change | Usual care: data collected 1 week prior to implementation; Adoption of teach-back; Baseline (pre-implementation); 1 month post-intervention; 2 months post-intervention; 3 months post-intervention
Caluya, 2021^36^; United States; 165 | Single site QI pre-post; Inpatient; Nurses working in facility; Heart Failure | Prepare sites for implementation; Train site staff and clinicians; Provide interactive assistance and site support | Educational intervention; Patient knowledge; heart failure readmissions; adoption of teach-back; 3 months post-intervention; 6 months post-intervention
Feinberg, 2019^37^; United States; 16 providers; 80 (clinic visits) | Single arm pilot study; Outpatient; family medicine and internal medicine residents; N/A | Train site staff and clinicians; Support clinician practice change | Usual care/pre-intervention; Perception of the use of teach-back; fidelity to teach-back; Post-intervention
Holman, 2019^38^; United States; 20 | Pre-post; In-patient; Nurses working at the facility treating patients; N/A | Train site staff and clinicians | Pre-intervention usual care; Conviction in the importance of using teach-back; confidence in the ability to use teach-back; Pre-intervention; Post-intervention
Klingbeil, 2018^39^; United States; 317 | Descriptive pre- and post-test; In-patient; Nurses, dieticians, respiratory care practitioners; occupational and physical therapists at a tertiary care 290-bed Magnet designated academic pediatric health care organization; N/A | Mobilize site staff for implementation; Tailor, iterate, and adapt to context; Prepare sites for implementation; Train site staff and clinicians | Pre-intervention usual care; Adoption of teach-back; Pre-intervention; Two-month follow-up; Ten to 12 month follow-up
Prochnow, 2019^40^; United States; 29 | Pre-post QI project; In-patient; RN providing care to patients on the trauma unit; N/A | Mobilize site staff for implementation; Tailor, iterate, and adapt to context; Prepare sites for implementation; Train site staff and clinicians; Support clinician practice change; Engage patients and families | Pre-intervention; Patient knowledge; patient satisfaction; conviction in the importance of teach-back; confidence in using teach-back; fidelity to teach-back; Pre-intervention; post-intervention
Scott, 2019^41^; United States; 19 | Pre-post; In-patient; Nurses treating oncology unit patients; Cancer | Train site staff and clinicians | Pre-intervention control; Patient satisfaction; Conviction; confidence; fidelity to teach-back; Immediately post-intervention; Cancer One month post-intervention; Three months post-intervention

## INTERVENTION CHARACTERISTICS

### KQ1

Author, Year; Design; Number of Study Conditions; Total Sample Size | Number of Participants in Comparator; Number of Participants in Intervention; Brief Intervention Description | Control Group Description; Single or Multi Behavior; Modalities Teach-Back Intervention was Administered via | Intervention Labeled as Teach-Back?; Actual Amount of Time Spent on Teach-Back; Who Delivered the Intervention
Berthelsen, 2020^47^; Randomized controlled trial; 2 | Participant received verbal information regarding (a) early mobilization and ambulation, (b) breathing exercises, (c) post-discharge physical activity and restrictions and asked to retell what they had heard | Received same information; were allowed to ask questions according to usual practice; Multi-behavior; Face-to-face | Yes; NA; Specialized physical therapist with several years experience of working within surgical care
Cetindemir, 2024^48^; Randomized controlled trial; 2; 100 | 50; 50; Participants received education and counseling based on the content of a Breastfeeding Education Guide and were asked to reiterate what they were taught | Standard education/usual care; Single; Face-to-face | Yes; NA; Researcher with 70 hrs of counseling education
Ghorbani, 2021^49^; Randomized controlled trial; 3; 123 | 41; 41; Teach-back intervention: Researcher delivered information and “corrected the patient’s misinformation.” | Usual care; second intervention using gamification; Multi-behavior; Face-to-face | Yes; 45-60 minutes; Researcher
Goni, 2024^25^; Randomized controlled trial; 2; 29 | 14; 15; Pharmacist interviewed participants regarding non-adherence and comprehension of medication plan and provided individualized information using the teach-back technique | Usual care, which included pharmacist undertaking medication reconciliation on admission and discharge, dispensing 4 weeks of medicines, preparation of a medication list, providing medication education, and liaising with other health professionals as required; Single-behavior; Verbal/telephone | Yes; NA; Pharmacist
Joseph, 2024^51^; Randomized controlled trial; 3; 120 | NA; NA; Standardized after visit instructions group (sAVI): participants received after visit instructions that were written using a standardized template; sAVI plus teach-back group: participants received the standardized (templated) after visit instructions and the patient then repeated back what changes and future management had been decided on during the visit | Usual care; Multi-behavior; NA | Yes; NA (5 out of 9 providers reported that typing the after visit instructions took 1-2 minutes); NA
Mesbahi, 2020^26^; Randomized controlled trial; 2; 80 | 40; 40; Four sessions of teach-back on self-care (content included information about diet, medication regimen, physical activity, weight control, fluid intake, warning signs of exacerbation, sleep, rest, methods of muscle relaxation) in which information was given and patients were asked to “were asked to recite the instructed materials in their language” | Active control. The control group received “conventional training” during education sessions instead of teach-back. Both groups received 4 30-60 minute education sessions and a booklet continaing training session materials.; Multi-behavior; Face-to-face | Yes; Unknown; Researcher
Nas, 2021^52^; Randomized controlled trial; 2; 70 | 35; 35; Participants received information about diabetes and “were asked to explain new information in their own words” | Usual diabetes education (w/o teach-back); Multi-behavior; Face-to-face | Yes; Mean diabetes education time was 47.2 ± 4.2 minutes; Health care professional
Oh, 2023^23^; Randomized controlled trial; 2; 100 | 50; 50; Participants received a 15 minute educational session (HEART program) including 7 heart failure related topics (definition of heart failure, medication, symptom management, weight management, dietary management, physical activity, and other precautions). After the session, participants were asked 15 pre-structured teach-back questions. | Usual care - 15 minute face-to-face discharge education on same topics but without teach-back method; no written materials; Multi-behavior; Face-to-face | Yes; NR; Nurse
Press, 2020^53^; Randomized controlled trial; 2; 121 | 61; 60; In-person teach-back group: Up to 3 rounds of inhaler education technique followed by comprehension assessments | Virtual asynchronous self-assessment questions; Single-behavior; Face-to-face | No; mean (SD) 9.7 minutes (4.4); Research educator
Rahmani, 2020^54^; Randomized controlled trial; 2; 70 | 35; 35; Participants received information on heart failure (symptoms, symptom management, salt intake, fluid intake, exercise, medication, daily weights, warning signs) after which “the patient was asked to give feedback to the nurse on what he/she had learned” | Routine care; Multi-behavior; Face-to-face | Yes; 30 min (20-40 min); Nurse
Saadatian, 2022^55^; Randomized controlled trial; 2; 100 | 50; 50; Participants received 3 sessions (session topics: illness perception, self-efficacy, and overview) each of which was followed by being asked to “repeat the instructed concept or topic in their own words” | Usual care (described as “routine training”) and also received the same educational booklet that the intervention group received; Multi-behavior; Face-to-face | Yes; 90 to 135 minutes total (each of the 3 sessions were 30-45 minutes); Researcher
Satehi, 2021^56^; Randomized controlled trial; 3; 90 | 30 each; 30; Single session of a one-on-one educational program about diabetic foot ulcer self care; at the end of the session, participants were asked to “retell the material in their own words as they understood it” at the end of the session. | Active control and usual care; Multi-behavior; Face-to-face | Yes; NA; Researcher
Shen, 2023^57^; Randomized controlled trial; 2; 116 | 58; 58; Distributed preoperative education manuals (including information such as surgical methods and medications, and skills/technique descriptions such as techniques for coughing/sneezing during surgery) after which participants were asked to review the content verbally with the interventionist or demonstrate a described technique. | Usual care; Multi-behavior; Face-to-face | Yes; NA; Nurse or deputy chief doctor
Teshnizi, 2024^58^; Randomized controlled trial; 2; 90 | 45; 45; Educational booklet with information about diabetes medical care and lifestyle management (from American Diabetes Association 2019 guidelines) provided to participants face-to-face after which each participant was asked to express their understanding of the material | Usual care; Multi-behavior; Face-to-face | Yes; NA; Researcher
Tran, 2019^59^; Randomized controlled trial; 2; 70 | 32; 38; Education session regarding 4 domains of chronic hepatitis B (transmission, natural history, epidemiology and prevention, and clinical management) including The Hepatitis B Story (a low health literacy educational resource) with teach-back questions to confirm understanding after each concept was presented. | Usual care via routine, standard appointment with gastroenterologist.; Multi-behavior; Face-to-face | Yes; Median (IQR): 15 (12, 22) min; Gastroenterologist or gastroenterology advanced trainee registrar; session run by a trained investigator (ST) using the teach-back strategy
Griffey, 2015^50^; Randomized controlled trial; 2; 408 | 196; 212; For patients in the intervention group, a medical student research assistant accompanied the patient’s nurse in the patient’s room while the nurse gave discharge instructions. After the nurse gave the instructions, the research assistant asked the patient to repeat back their understanding in their own words. and the nurse would correct misunderstandings. | Standard discharge; Multi-behavior; Face-to-face | Yes; NA; Medical students and nursing staff

### KQ2

Author, Year; Design; Number of Study conditions; Total Sample Size | Number of Participants in the Comparator; Number of Participants in the Intervention; Brief Intervention Description | Description of Comparator; Single or Multi-Behavior; Modalities Teach-Back Intervention was Delivered Via | Labeled Teach-Back?; Time Spent on Teach-Back; Training of Person Who Delivered Intervention | Description of Implementation Strategy; Was Fidelity to Teach-Back Assesed?
Burmeister, 2022^35^; Quality improvement project- pre-post; 1; 0 | NA; NA; Distribution of written patient education materials at admission and throughout hospitalization | Usual care: Data were collected 1 week prior to implementation.; Multi-behavioral; NA | Yes; NA; Nursing | 1. Each RN on the unit was able to review the educational handouts to provide feedback and make suggestions for change before implementation.; 2. The project was adapted from its initial version to allow for nurses to have greater time and opportunity to engage in teach-back; 3. The RNs were individually educated on the quality improvement process through verbal communication. Lastly, the nurses were encouraged to provide feedback or recommendations throughout implementation; Yes
Caluya, 2021^36^; Single site QI pre-post; 1; 165 | NA; 165; Two hour class for nurses on the topics of heart failure self-management and the teach-back method, and optional observation (with feedback) of nurses providing heart failure education to patients | NA; Multi-behavioral; NA | Yes; NA; Nurse | Prepare: Used observation tool Train: Education sessions on heart failure self-management and use of teach-back.; Interactive Assistance: Observation and feedback
Feinberg, 2019^37^; Single arm pilot study; 1; 0 | NA; Clinicians: 16; One hour teach-back skills training course for medical residents | Pre-intervention; Single-behavior; Face-to-face | Yes; NA; The primary investigator did the training | Residents attended a 1-hour training focused on teach-back.
Carita K. Holman, 2019^38^; Pre-post; 1; 20 | 0; 20; Several coaching sessions on teach-back using material from the Agency for Healthcare Research and Quality’s Health Literacy Universal Precautions Toolkit and the Always Use Teach-Back! Toolkit | NA; Multi-behavior as it focused on teach-back techniques in general.; NA | Yes; NA; License practical nurses, registered nurses, nurse case managers, and nurse practitioners on 2 medical-surgical nursing units | Training of staff
Klingbeil, 2018^39^; Descriptive pre and post-test; 1; 317 | NA; 317; Interactive teaching session for clinical staff about low health literacy, using open-ended questions, and how to use teach-back with patients and families | NA; NA; NA | Yes; NA; Nursing, respiratory therapists, dieticians, physical therapists, occupational therapists | Initial 2 site pilot supported by an education grant; staff formed a special interest group; pilot established benefits for patients and staff and sustainability explored; utilization of organizational patient satisfaction scores and safety events; organizational buy-in obtained; then scheduling of training as noted.
Prochnow, 2019^40^; Pre-post QI project; 1; 29 | NA; 29; Each participating RN received a 10-20 minute education session on the use of teach-back (included information about the problem of patients reporting inadequate education on new medications; an overview of prior observations about RN use of teach-back; a handout and discussion on “10 Elements of Competence for Using Teach-back Effectively;” a 2-minute Institute for Health care Improvement video on teach-back; and role playing) | NA; Multi-behavior; Video | Yes; NA; Nurses | Mobilize: Project leaders met with Unit Practice Council; Tailoring: They denote it was tailored, but did not specific how.; Prepare: Assessment of practice environment; Train: The tools include always Use Teach-Back Toolkit.; Support: Reminder cards that included timeline and activities as well as ongoing emails. Ongoing coaching.; Engage: Patients/Caregivers approached and signed consent.
Scott, 2019^41^; Pre-post; 1; 19 | NA; 19; Mandatory 1-hour class for nurses on the teach-back method; curriculum based on Institute for Healthcare Improvement (2016) Always Events toolkit; class included didactics, demonstration, and simulation. During a “skill development window” 2-week period after completing the class, nurses were observed by nurse educators to evaluate their use of teach-back and have the opportunity to ask questions with the research team using this period of time to address barriers to use of teach-back. | NA; Multi-behavior; Teach-back interactions were observed by a clinical nurse educator; I think face-to-face encounters are implied | Yes; 1 hour; amount of observation time unclear; Nurses | Train Site Staff and Clinicians: Following class session nurses participated in a role play clinical simulation and received feedback. Study had a 2 week observation window during which nurses could ask follow-up questions and barriers to teach-back could be addressed by the research team.

## RESULTS KQ1

### KNOWLEDGE

Author, Year; Total Number Analyzed; Setting; Multi-Behavior versus Single Behavior | Outcome Measure | Baseline; Intervention: Results; Control: Results; Follow-Up Time Point; Intervention: Results; Control: Results; Effect Estimate; P Value; 95% CI
Press, 2020 ^53^; N = 118; Inpatient; Single-behavior | Understanding and knowledge- (model 2) correct inhaler use technique | Baseline; Intervention: 10/59; Control: 1/59; Follow-up time point (0 days); Intervention: 49/59; Control: 41/59; Effect estimate difference in proportion (Control versus intervention): −0.1; SE 0.07; 95% CI (−0.22, NA)
Press, 2020 ^53^; N = 118; Inpatient; Single-behavior | Understanding and knowledge- (model 3) correct inhaler score | Baseline; Intervention: 10/59; Control: 1/59; Follow-up time point (0 days); Intervention: 49/59; Control: 41/59; Effect estimate difference in proportion (Control versus intervention): −0.11; SE 0.05; 95% CI (−0.19, NA)
Press, 2020 ^53^; N = 118; Inpatient; Single-behavior | Understanding and knowledge- (model 2) correct inhaler use technique | Baseline; Intervention: 10/59; Control: 1/59; Follow-up time point (30 days); Intervention: 32/51; Control: 26/49; Effect estimate difference in proportion (Control versus intervention): −0.04; SE 0.09; 95% CI (−0.18, NA)
Press, 2020 ^53^; N = 118; Inpatient; Single-behavior | Understanding and knowledge- (model 3) correct inhaler score | Baseline; Intervention: 10/59; Control: 1/59; Follow-up time point (30 days); Intervention: 32/51; Control: 26/49; A; Effect estimate difference in proportion (Control versus intervention): −0.12; SE 0.07; 95% CI (−0.23, NA)
Berthelsen, 2020^47^; N = 48; Outpatient; Multi-behavior | Understanding and knowledge- recall of 29 statements | Baseline NA; Follow-up time point (2 to 4 days); Intervention: Mean 9.5 (1 to 15 range); Mean 7 (0 to 13 range); Effect estimate: NA; p = .214
Goni, 2024^25^; N = 29; Outpatient; Single-behavior | Understanding and knowledge | Baseline; Intervention:; Mean 58 (SD NR); Control:; Mean 48 (SD NR); Follow-up time point (12 weeks); Intervention:; Mean 9 (SD NR); Control:; Mean 4821 (SD NR); Effect estimate F statistic: 16.57; eta squared: 0.38; p < .001
Joseph, 2024^51^; N = 75; Outpatient; Multi-behavior | Understanding and knowledge (complete and most concordance in understanding of medication changes/side effects ) | Baseline: NA; Follow-up time point (7 to 14 days); Intervention: 21/25; Control: 14/19; Effect estimate: NA; p = .27
Joseph, 2024^51^; N = 75; Outpatient; Multi-behavior | Understanding and knowledge (complete and most concordance in understanding of reason for visit) | Baseline: NA; Follow-up time point (7 to 14 days); Intervention: 22/25; Control: 19/19; Effect estimate: NA; p = .399
Joseph, 2024^51^; N = 75; Outpatient; Multi-behavior | Understanding and knowledge (complete and most concordance in understanding of referrals and diagnostics) | Baseline: NA; Follow-up time point (7 to 14 days); Intervention: 14/25; Control: 11/19; Effect estimate: NA; p = .63
Joseph, 2024^51^; N = 75; Outpatient; Multi-behavior | Understanding and knowledge (complete concordance in understanding of medication changes/side effects) | Baseline NA; Follow-up time point (7 to 14 days); Intervention: 17/25; Control: 7/19; Effect estimate: NA; p = .27
Joseph, 2024^51^; N = 75; Outpatient; Multi-behavior | Understanding and knowledge (complete concordance in understanding of medication changes/side effects) | Baseline: NA; Follow-up time point (7 to 14 days); Intervention: 17/25; Control: 11/31; Effect estimate: NA; p = .27
Joseph, 2024^51^; N = 75; Outpatient; Multi-behavior | Understanding and knowledge (complete concordance in understanding of reason for visit) | Baseline: NA; Follow-up time point (7 to 14 days); Intervention: 18/25; Control: 16/19; Effect estimate: NA; p = .399
Joseph, 2024^51^; N = 75; Outpatient; Multi-behavior | Understanding and knowledge (complete concordance in understanding of reason for visit) | Baseline: NA; Follow-up time point (7 to 14 days); Intervention: 18/25; Control: 18/31; Effect estimate: NA; p = .399
Joseph, 2024^51^; N = 75; Outpatient; Multi-behavior | Understanding and knowledge (complete concordance in understanding of referrals and diagnostics) | Baseline: NA; Follow-up time point (7 to 14 days); Intervention: 13/25; Control: 10/19; Effect estimate: NA; p = .63
Joseph, 2024^51^; N = 75; Outpatient; Multi-behavior | Understanding and knowledge (complete concordance in understanding of referrals and diagnostics) | Baseline NA; Follow-up time point (7 to 14 days); Intervention: 13/25; Control: 12/31; Effect estimate: NA; p = .63
Joseph, 2024^51^; N = 75; Outpatient; Multi-behavior | Understanding and knowledge (minimal concordance in understanding of medication changes/side effects) | Baseline: NA; Follow-up time point (7 to 14 days); Intervention: 0/25; Control: 2/19; Effect estimate: NA; p = .27
Joseph, 2024^51^; N = 75; Outpatient; Multi-behavior | Understanding and knowledge (minimal concordance in understanding of medication changes/side effects) | Baseline: NA; Follow-up time point (7 to 14 days); Intervention: 0/25; Control: 3/31; Effect estimate NA; p = .27
Joseph, 2024^51^; N = 75; Outpatient; Multi-behavior | Understanding and knowledge (minimal concordance in understanding of reason for visit) | Baseline: NA; Follow-up time point (7 to 14 days); Intervention: 0/25; Control: 0/19; Effect estimate: NA; p = .399
Joseph, 2024^51^; N = 75; Outpatient; Multi-behavior | Understanding and knowledge (minimal concordance in understanding of reason for visit) | Baseline: NA; Follow-up time point (7 to 14 days); Intervention: 0/25; Control: 1/31; Effect estimate: NA; p = .399
Joseph, 2024^51^; N = 75; Outpatient; Multi-behavior | Understanding and knowledge (minimal concordance in understanding of referrals and diagnostics) | Baseline: NA; Follow-up time point (7 to 14 days); Intervention: 1/25; Control: 0/19; Effect estimate: NA; p = .63
Joseph, 2024^51^; N = 75; Outpatient; Multi-behavior | Understanding and knowledge (minimal concordance in understanding of referrals and diagnostics) | Baseline: NA; Follow-up time point (7 to 14 days); Intervention: 1/25; Control: 2/31; Effect estimate: NA; p = .63
Joseph, 2024^51^; N = 75; Outpatient; Multi-behavior | Understanding and knowledge (most concordance in understanding of medication changes/side effects) | Baseline: NA; Follow-up time point (7 to 14 days); Intervention: 4/25; Control: 7/19; Effect estimate: NA; p = .27
Joseph, 2024^51^; N = 75; Outpatient; Multi-behavior | Understanding and knowledge (most concordance in understanding of medication changes/side effects) | Baseline: NA; Follow-up time point (7 to 14 days); Intervention: 4/25; Control: 4/31; Effect estimate: NA; p = .27
Joseph, 2024^51^; N = 75; Outpatient; Multi-behavior | Understanding and knowledge (most concordance in understanding of reason for visit) | Baseline: NA; Follow-up time point (7 to 14 days); Intervention: 4/25; Control: 3/19; Effect estimate: NA; p = .399
Joseph, 2024^51^; N = 75; Outpatient; Multi-behavior | Understanding and knowledge (most concordance in understanding of reason for visit) | Baseline: NA; Follow-up time point (7 to 14 days); Intervention: 4/25; Control: 9/31; Effect estimate: NA; p = .399
Joseph, 2024^51^; N = 75; Outpatient; Multi-behavior | Understanding and knowledge (most concordance in understanding of referrals and diagnostics) | Baseline: NA; Follow-up time point (7 to 14 days); Intervention: 1/25; Control: 1/19; Effect estimate: NA; p = .63
Joseph, 2024^51^; N = 75; Outpatient; Multi-behavior | Understanding and knowledge (most concordance in understanding of referrals and diagnostics) | Baseline: NA; Follow-up time point (7 to 14 days); Intervention: 1/25; Control: 2/31; Effect estimate: NA; p = .63
Joseph, 2024^51^; N = 75; Outpatient; Multi-behavior | Understanding and knowledge (partial concordance in understanding of medication changes/side effects) | Baseline: NA; Follow-up time point (7 to 14 days); Intervention: 1/25; Control: 3/19; Effect estimate: NA; p = .27
Joseph, 2024^51^; N = 75; Outpatient; Multi-behavior | Understanding and knowledge (partial concordance in understanding of medication changes/side effects) | Baseline: NA; Follow-up time point (7 to 14 days); Intervention: 1/25; Control: 1/31; Effect estimate: NA; p = .27
Joseph, 2024^51^; N = 75; Outpatient; Multi-behavior | Understanding and knowledge (partial concordance in understanding of reason for visit) | Baseline: NA; Follow-up time point (7 to 14 days); Intervention: 3/25; Control: 0/19; Effect estimate: NA; p = .399
Joseph, 2024^51^; N = 75; Outpatient; Multi-behavior | Understanding and knowledge (partial concordance in understanding of reason for visit) | Baseline: NA; Follow-up time point (7 to 14 days); Intervention: 3/25; Control: 3/31; Effect estimate: NA; p = .399
Joseph, 2024^51^; N = 75; Outpatient; Multi-behavior | Understanding and knowledge (partial concordance in understanding of referrals and diagnostics) | Baseline: NA; Follow-up time point (7 to 14 days); Intervention: 1/25; Control: 3/19; Effect estimate: NA; p = .63
Joseph, 2024^51^; N = 75; Outpatient; Multi-behavior | Understanding and knowledge (partial concordance in understanding of referrals and diagnostics) | Baseline: NA; Follow-up time point (7 to 14 days); Intervention: 1/25; Control: 1/31; Effect estimate: NA; p = .63
Nas, 2021^52^; N = 61; Outpatient; Multi-behavior | Understanding and knowledge- DKL instrument instrument | Baseline; Intervention: Mean 10.2 (2.1 SD); Control: Mean 11.2 (2.3 SD); Follow-up time point (immediately after intervention); Intervention: Mean 16.9 (2.1 SD); Control: Mean 14.1 (2 SD); Effect estimate: NA; p < .001
Nas, 2021^52^; N = 61; Outpatient; Multi-behavior | Understanding and knowledge- DKL instrument | Baseline; Intervention: Mean 10.2 (2.1 SD); Control: Mean 11.2 (2.3 SD); Follow-up time point (3 months after intervention); Intervention: Mean 15.2 (2.7 SD); Control: Mean 12.2 (1.9 SD); Effect estimate: NA; p < .001
Shen, 2023^57^; N = 116; Outpatient; Multi-behavior | Understanding and knowledge- Total score of awareness of health education | Baseline: NA; Follow-up time point (Perioperative) NA; Intervention: Mean 53.19 (6.42 SD); Control: Mean 47.45 (8.1 SD); Effect estimate t/Z value: 4.23; p = 0
Shen, 2023^57^; N = 116; Outpatient; Multi-behavior | Understanding and knowledge; basically know | Baseline: NA; Follow-up time point (Perioperative); Intervention: 22/58; Control: 26/58 Effect estimate: NA
Shen, 2023^57^; N = 116; Outpatient; Multi-behavior | Understanding and knowledge; don’t know | Baseline: NA; Follow-up time point (Perioperative); Intervention: 0/58; Control: 8/58; Effect estimate: NA
Shen, 2023^57^; N = 116; Outpatient; Multi-behavior | Understanding and knowledge; know | Baseline: NA; Follow-up time point (Perioperative); Intervention: 36/58; Control: 24/58; Effect estimate t/Z value: −2.71; p = .007
Tran, 2019^59^; N = 70 (51 at 1 month follow-up); Outpatient; Multi-behavior | Understanding and knowledge- Combined knowledge score assessed via the chronic hepatitis B questionnaire | Baseline; Intervention: Mean 18.7 (SD NA) Median: 19 (IQR: 17.75 to 20); Control: Mean 19.4 (SD NA) Median: 19.5 (IQR: 18.25 to 21); Follow-up time point (early recall); Intervention: Mean 22.5 (SD NA); Control: Mean 19.6 (SD NA); Effect estimate: NA
Tran, 2019^59^; N = 70 (51 at 1 month follow-up); Outpatient; Multi-behavior | Understanding and knowledge- Combined knowledge score assessed via the chronic hepatitis B questionnaire | Baseline; Intervention: Mean 18.7 (SD NA) Median: 19 (IQR: 17.75 to 20); Control: Mean 19.4 (SD NA) Median: 19.5 (IQR: 18.25 to 21); Follow-up time point (1 month); Intervention: Mean 21.9 (SD NA) Median: 22 (IQR: 21 to 23); Control: Mean 19.5 (SD NA) Median: 19 (IQR: 18 to 21.75); Effect estimate: NA; p > .65 (comparator change from baseline); p < .001 (intervention change from baseline)
Tran, 2019^59^; N = 70 (51 at 1 month follow-up); Outpatient; Multi-behavior | Understanding and knowledge-Transmission domain knowledge score assessed via the chronic hepatitis B questionnaire | Baseline; Intervention: Mean 7.1 (1.6 SD); Control: Mean 7.4 (1.3 SD); Follow-up time point (early recall); Intervention: Mean 8.9 (0.4 SD); Control: Mean 7.4 (1.3 SD); Effect estimate: NA
Tran, 2019^59^; N = 70 (51 at 1 month follow-up); Outpatient; Multi-behavior | Understanding and knowledge- Natural history domain knowledge score assessed via the chronic hepatitis B questionnaire | Baseline; Intervention: Mean 4.5 (0.8 SD); Control: Mean 4.6 (0.7 SD); Follow-up time point (early recall); Intervention: Mean 5 (0 SD); Control: Mean 4.8 (0.5 SD); Effect estimate: NA
Tran, 2019^59^; N = 70 (51 at 1 month follow-up); Outpatient; Multi-behavior | Understanding and knowledge-Epidemiology & Prevention domain knowledge score assessed via the chronic hepatitis B questionnaire | Baseline; Intervention: Mean 3.9 (0.7 SD); Control: Mean 4.1 (0.6 SD); Follow-up time point (early recall); Intervention: Mean 4.8 (0.5 SD); Control: Mean 4.1 (0.6 SD); Effect estimate: NA
Tran, 2019^59^; N = 70 (51 at 1 month follow-up); Outpatient; Multi-behavior | Understanding and knowledge- Clinical Management domain knowledge score assessed via the chronic hepatitis B questionnaire | Baseline; Intervention: Mean 3.2 (0.9 SD); Control: Mean 3.4 (0.7 SD); Follow-up time point (early recall); Intervention: Mean 3.8 (0.5 SD); Control: Mean 3.3 (0.9 SD); Effect estimate: NA
Griffey, 2015^50^; N = 408; Outpatient; Multi-behavior | Understanding and knowledge - Provider assessed patient understanding of diagnosis | Baseline: NA; Follow-up time point: NA; Effect estimate OR: 1.35; p = .25; 95% CI (0.81, 2.25)
Griffey, 2015^50^; N = 408; Outpatient; Multi-behavior | Understanding and knowledge - Provider assessed patient understanding of testing in ED | Baseline: NA; Follow-up time point: NA; Effect estimate OR: 1.01; p = .96; 95% CI (0.6, 1.72)
Griffey, 2015^50^; N = 408; Outpatient; Multi-behavior | Understanding and knowledge - Provider assessed patient understanding of treatments in ED | Baseline: NA; Follow-up time point: NA; Effect estimate OR: 1.6; p = .08; 95% CI (0.94, 2.73)
Griffey, 2015^50^; N = 408; Outpatient; Multi-behavior | Understanding and knowledge- Patient perceived difficulty with ED care | Baseline: NA; Follow-up time point: NA; Effect estimate OR: 0.78; p = .44; 95% CI (0.41, 1.47)
Griffey, 2015^50^; N = 408; Outpatient; Multi-behavior | Understanding and knowledge- Patient perceived difficulty with return instructions | Baseline: NA; Follow-up time point: NA; Effect estimate OR: 0.91; p = .76; 95% CI (0.47, 1.74)
Griffey, 2015^50^; N = 408; Outpatient; Multi-behavior | Understanding and knowledge- Patient perceived difficulty with self-care | Baseline: NA; Follow-up time point: NA; Effect estimate OR: 1.18; p = .67; 95% CI (0.56, 2.5)
Griffey, 2015^50^; N = 408; Outpatient; Multi-behavior | Understanding and knowledge - Patient perceived understanding of difficulty with diagnosis | Baseline: NA; Follow-up time point: NA; Effect estimate OR: 0.68; p = .17; 95% CI (0.4, 1.17)
Griffey, 2015^50^; N = 408; Outpatient; Multi-behavior | Understanding and knowledge- Patient perceived understanding of ED care | Baseline: NA; Follow-up time point: NA; Effect estimate OR: 1.13; p = .61; 95% CI (0.71, 1.81)
Griffey, 2015^50^; N = 408; Outpatient; Multi-behavior | Understanding and knowledge- Patient perceived understanding of return instructions | Baseline: NA; Follow-up time point: NA; Effect estimate OR: 1.15; p = .57; 95% CI (0.71, 1.84)
Griffey, 2015^50^; N = 408; Outpatient; Multi-behavior | Understanding and knowledge- Patient perceived understanding of self-care | Baseline: NA; Follow-up time point: NA; Effect estimate OR: 1.43; p = .15; 95% CI (0.88, 2.33)
Griffey, 2015^50^; N = 408; Outpatient; Multi-behavior | Understanding and knowledge - Provider assessed patient understanding of perceived understanding of diagnosis | Baseline: NA; Follow-up time point: NA; Effect estimate OR: 0.99; p = .97; 95% CI (0.62, 1.58)
Griffey, 2015^50^; N = 408; Outpatient; Multi-behavior | Understanding and knowledge - Provider assessed patient understanding of post-ED follow-up | Baseline: NA; Follow-up time point: NA; Effect estimate OR: 3.61; p < .0001; 95% CI (2.09, 6.22)
Griffey, 2015^50^; N = 408; Outpatient; Multi-behavior | Understanding and knowledge - Provider assessed patient understanding of post-ED selfcare | Baseline: NA; Follow-up time point: NA; Effect estimate OR: 1.83; p = .03; 95% CI (1.07, 3.13)
Griffey, 2015^50^; N = 408; Outpatient; Multi-behavior | Understanding and knowledge- Provider assessed patient understanding of return instructions | Baseline: NA; Follow-up time point: NA; Effect estimate OR: 1.26; p = .37; 95% CI (0.76, 2.07)
Griffey, 2015^50^; N = 408; Outpatient; Multi-behavior | Understanding and knowledge- Provider assessed patient understanding of post-ED medications | Baseline: NA; Follow-up time point: NA; Effect estimate OR: 1.84; p = .02; 95% CI (1.09, 3.12)

### ADHERENCE RESULTS

Author, Year; Setting; Multi-Behavior versus Single Behavior | Outcome Measure | Baseline; Intervention: Results; Control: Results; Follow-Up Time Point; Intervention: Results; Control: Results; Effect Estimate; P Value; 95% CI
Çetindemir, 2024^48^; Inpatient; Single-behavior | Adherence to breastfeeding using LATCH scale | Baseline; Intervention: Mean 7.73 (1.81 SD); Control: Mean 8.33 (2.08 SD); Follow-up time point (1 day); Intervention: Mean 8.66 (1.61 SD); Control: Mean 8.55 (1.72 SD); Summary estimate Z score: −0.19; p = .85
Çetindemir, 2024^48^; Inpatient; Single-behavior | Adherence to breastfeeding using LATCH scale | Baseline; Intervention: Mean 7.73 (1.81 SD); Control: Mean 8.33 (2.08 SD); Follow-up time point (1 month); Intervention: Mean 9.95 (0.3 SD); Control: Mean 8.77 (1.67 SD); Summary estimate Z score: −4.55; p < .001
Ghorbani, 2021^49^; Inpatient; Multi-behavior | Adherence to dietary regimen | Baseline: N/A; Follow-up time point (1-month); Intervention: Mean −0.35 (0.7 Sd); Control: Mean −0.76 (0.52 SD); Mean difference: 0.42 (0.16 SE); p = .021; 95% CI (0.06, 0.78)
Ghorbani, 2021^49^; Inpatient; Multi-behavior | Adherence to exercise regimen | Baseline: N/A; Follow-up time point (1-month); Intervention: Mean −0.27 (0.53 SD); Control: Mean −0.91 (0.33 SD); mean difference: 0.64 (0.13 SE); p <.001; 95% CI (0.33, 0.94)
Ghorbani, 2021^49^; Inpatient; Multi-behavior | Adherence to medication regimen | Baseline: N/A; Follow-up time point (1-month); Intervention: Mean −0.2 (1.11 SD); Control: Mean −0.40 (0.68 SD); Mean difference: 0.2 (0.24 SE); p = .61; 95% CI (−0.33, 0.73)
Mesbahi, 2020^26^; Inpatient; Multi- behavior | Adherence to European heart failure self-care behavior scale | Baseline; Intervention: Mean 41.17 (15.56 SD); Control: Mean 43.05 (12.03 SD); Follow-up time point (3 months); Intervention: Mean 33.9 (17.43 SD); Control: Mean 41.15 (12.82 SD); Effect estimate T test: 2.2 df = 78; p = .03
Goni, 2024^25^; Outpatient; Single- behavior | Adherence using Morisky Medication Adherence Scale | Baseline; Intervention: Mean 6.7 (SD NR); Control: Mean 7.4 (SD NR); Follow-up time point (12 weeks); Intervention: Mean 7.6 (SD NR); Control: Mean 6.9 (SD NR); Effect estimate eta squared: 0.29; p = .003
Teshnizi, 2024^58^; Outpatient; Multi-behavior | Adherence to treatment | Baseline; Intervention: Mean 11.49 (120.52 SD); Control: Mean 16.89 (113.38 SD); Follow-up time point (1 week); Intervention: Mean 18.8 (140.65 SD); Control: Mean 18.47 (145.02 SD); Effect estimate F statistic:1.97; p = .16
Teshnizi, 2024^58^; Outpatient; Multi-behavior | Adherence to treatment | Baseline; Intervention: Mean 11.49 (120.52 SD); Control: Mean 16.89 (113.38 SD); Follow-up time point (40 days); Intervention: Mean 18.8 (140.65 SD); Control: Mean 18.47 (145.02 SD); Effect estimate F statistic: 122.85; p = .001

### SELF-EFFICACY RESULTS

Author, Year; Total Number Analyzed; Setting; Multi-Behavior versus Single Behavior | Outcome Measure | Baseline; Intervention: Results; Control: Results; Follow-Up Time Point Intervention: Results; Control: Results; Effect Estimate; P Value; 95% CI
Çetindemir, 2024^48^; N = 48; Inpatient; Single-behavior | Self-efficacy/confidence- Breastfeeding Self-Efficacy measured by Postpartum Breastfeeding Self-Efficacy Scale (short form) | Baseline; Intervention: Mean 46.41 (11.26 SD); Control: Mean 48.77 (14.71 SD); Follow-up time point (1 day); Intervention: Mean 66.23 (6.94 SD); Control: Mean 50.86 (13.98 SD); Effect estimate Z: −6.29; p < .001
Çetindemir, 2024^48^; N = 48; Inpatient; Single-behavior | Self-efficacy/confidence- Breastfeeding Self-Efficacy measured by Postpartum Breastfeeding Self-Efficacy Scale (short form) | Baseline; Intervention: Mean 46.41 (11.26 SD); Control: Mean 48.77 (14.71 SD); Follow-up time point (1 month); Intervention: Mean 67.84 (6.27 SD); Control: Mean 49.7 (16.47 SD); Effect estimate Z: −7.18; p < .001
Oh, 2023^23^; N = 94; Inpatient; Multi-behavior | Self-care efficacy- Belief of one’s capability to perform self-care behaviors, was measured by the self-care self-efficacy scale | Baseline; Intervention: Mean 75.6 (20.1 SD); Control: Mean 77.2 (17.5 SD); Follow-up time point (1 week); Intervention: Mean 85 (1.76 Se); Control: Mean 80 (1.69 SE); Effect estimate F statistic: 4.21; p = .043
Rahmani, 2020^54^; N = 70; Inpatient; Multi-behavior | Self-efficacy- Cardiac self-care questionnaire | Baseline; Intervention: Mean 5.23 (2.67 SD); Control: Mean 4.37 (2.16 SD); Follow-up time point (immediately post); Intervention: Mean 9.37 (2.34 SD); Control: Mean 5.43 (1.77 SD); Effect estimate mean difference: 3.31; p < .001; 95% CI (2.78, 3.86)
Rahmani, 2020^54^; N = 70; Inpatient; Multi-behavior | Self-efficacy - Cardiac self-care questionnaire | Baseline; Intervention: Mean 5.23 (2.67 SD); Control: Mean 4.37 (2.16 SD); Follow-up time point (3 months); Intervention: Mean 10.03 (2.04 SD); Control: Mean 8 (1.64 SD); Effect estimate mean difference: 1.63; p < .001; 95% CI (0.94, 2.32)
Rahmani, 2020^54^; N = 70; Inpatient; Multi-behavior | Self-efficacy- Cardiac self-care questionnaire | Baseline; Intervention: Mean 14.77 (5.97 SD); Control: Mean 14.71 (6.39 SD); Follow-up time point (immediately post intervention); Intervention: Mean 25.26 (5.5 SD); Control: Mean 16.74 (5.68 SD); Effect estimate mean difference: 8.47; p < .001; 95% CI (7.42, 9.51)
Rahmani, 2020^54^; N = 70; Inpatient; Multi-behavior | Self-efficacy- Cardiac self-care questionnaire | Baseline; Intervention: Mean 14.77 (5.97 SD); Control: Mean 14.71 (6.39 SD); Follow-up time point (3 months); Intervention: Mean 28.14 (4.91 SD); Control: Mean 26.06 (3.36 SD); Effect estimate mean difference: 2.06; p < .001; 95% CI (0.82, 3.29)
Saadatian, 2022^55^; N = not reported; Inpatient; Multi-behavior | Self-efficacy- Cardiovascular Management Self-efficacy Scale | Baseline; Intervention: Mean 34.34 (5.25 SD); Control: Mean 31.94 (3.98 SD); Follow-up time point (1 month); Intervention: Mean 37.26 (4.17 SD); Control: Mean 33.93 (4.4 SD); Effect estimate F statistic: 73.4; p = .001
Satehi, 2021^56^; N = 90; Inpatient; Multi-behavior | Self-efficacy- Diabetes management self-efficacy scale (DMSES) evaluating self-care and related behaviors (eg, diet, exercise, blood glucose testing, foot care, and smoking) | Baseline; Intervention: Mean 42.46 (14.38 SD); Multimedia active control: Mean 41.6 (12.97 SD); Follow-up time point (2 weeks); Intervention: Mean 58.42 (11.38 SD); Multimedia active control: Mean 60.26 (6.7 SD); Effect estimate F statistic: N/A; p < .001
Satehi, 2021^56^; N = 90; Inpatient; Multi-behavior | Self-efficacy- Diabetes management self-efficacy scale (DMSES) evaluating self-care and related behaviors (eg, diet, exercise, blood glucose testing, foot care, and smoking) | Baseline; Intervention: Mean 42.46 (14.38 SD); Usual care control: Mean 41.23 (41.6 SD); Follow-up time point (2 weeks); Intervention: Mean 58.42 (11.38 SD); Usual care control: Mean 41.6 (9.18 SD); Effect estimate F statistic: N/A; p < .001

### PATIENT SATISFACTION RESULTS

Author, Year; Setting; Multi-Behavior versus Single Behavior | Outcome Measure | Baseline; Intervention: Results; Control: Results; Time Point; Intervention: Results; Control: Results; Effect Estimate; P Value; 95% CI
Griffey, 2015^50^; Outpatient; Multi-behavior | Satisfaction: would recommend this ED to a friend | Baseline; Intervention: Counts NR; Control: Counts NR; Time point (End of intervention); Intervention: Counts NR; Control: Counts NR; OR: 0.94; p = .81; 95% CI (0.56, 1.57)
Griffey, 2015^50^; Outpatient; Multi-behavior | Satisfaction with instructions | Baseline; Intervention: Counts NR; Control: Counts NR; Time point (End of intervention); Intervention: Counts NR; Control: Counts NR; OR: 0.73; p = .349; 95% CI (0.38, 1.42)
Griffey, 2015^50^; Outpatient; Multi-behavior | Satisfaction with discharge instructions | Baseline; Intervention: Counts NR; Control: Counts NR; Time point (End of intervention); Intervention: Counts NR; Control: Counts NR; OR: 0.78; p = .51; 95% CI (0.37, 1.65)
Griffey, 2015^50^; Outpatient; Multi-behavior | Satisfaction with ED time | Baseline; Intervention: Counts NR; Control: Counts NR; Time point (End of intervention); Intervention: Counts NR; Control: Counts NR; OR: 0.68; p = .19; 95% CI (0.39, 1.21)
Joseph, 2024^51^; Outpatient; Multi-behavior | Satisfaction: confident in provider’s ability | Baseline; Teach-back and standardized instructions: Counts NR; Standardized instructions: Counts NR; Time point (End of intervention); Teach-back and standardized instructions: 14/18; Standardized instructions: 7/14; Effect estimate: NR
Joseph, 2024^51^; Outpatient; Multi-behavior | Satisfaction: easy to understand | Baseline; Teach-back and standardized instructions: Counts NR; Standardized instructions: Counts NR; Time point (End of intervention); Teach-back and standardized instructions: 16/18; Standardized instructions: 7/14; Effect estimate: NR
Joseph, 2024^51^; Outpatient; Multi-behavior | Satisfaction: listened carefully | Baseline; Teach-back and standardized instructions: Counts NR; Standardized instructions: Counts NR; Time point (End of intervention); Teach-back and standardized instructions: 16/18; Standardized instructions: 7/14; Effect estimate: NR
Joseph, 2024^51^; Outpatient; Multi-behavior | Satisfaction: showed respect | Baseline; Teach-back and standardized instructions: Counts NR; Standardized instructions: Counts NR; Time point (End of intervention); Teach-back and standardized instructions:15/18; Standardized instructions: 10/14; Effect estimate: NR
Joseph, 2024^51^; Outpatient; Multi-behavior | Satisfaction: spent enough time | Baseline; Teach-back and standardized instructions: Counts NR; Standardized instructions: Counts NR; Time point (End of intervention); Teach-back and standardized instructions: 16/18; Standardized instructions: 10/14; Effect estimate: NR

## OUTCOMES MAPPING KQ1

Author, Year | Proximal Outcome 1 | Proximal Outcome 2 | Intermediate Outcome 1 | Intermediate Outcome 2 | Intermediate Outcome 3 | Distal Outcome 1 | Distal Outcome 2 | Distal Outcome 3 | Distal Outcome 4 | Distal Outcome 5
Berthelsen 2020^47^ | Knowledge | | | | | Length of stay
Centindemir 2024^48^ | | | Self-efficacy | Adherence
Ghorbani 2021^49^ | | | Adherence
Goni 2024^25^ | Knowledge | | Adherence | | | Hospital readmission | Use of secondary cardioprotective medications | Attendance at cardiac rehab
Griffey 2015^50^ | Knowledge | Patient satisfaction
Joseph 2024 Joseph, 2024 #13} | Knowledge | Patient satisfaction | | | | Provider satisfaction | Feasibility
Mesbahi 2020^26^ | | | Adherence | | | Hospital readmission | Number of Doctor visits
Nas 2021^52^ | Knowledge | | | | | Hgb A1c | Fasting glucose | Blood pressure
Oh 2023^23^ | | | Self-care efficacy | | | Heart failure symptoms | Readmissions | ER visits | Outpatient department visits | Contact with health care professionals
Press 2020^53^ | Knowledge | | | | | Emergency department visits
Rahmani 2020^54^ | | | Self-efficacy | | | Quality of life | Readmission
Saadatian 2022^55^ | | | Self-efficacy
Satehi 2021^56^ | | | Self-efficacy
Shen 2023^57^ | Knowledge | | Adherence | | | Pre-operative anxiety | Blood Pressure | Heart rate
Teshnizi 2024^58^ | | | Adherence
Tran 2019^59^ | Knowledge

## DATA EXTRACTION METHODS ELEMENTS

Aim of Study

Number of Study Conditions

Conflicts of interest declared by first or last author

Detailed intervention description, including a brief description of the educational content covered

Was the education content covered single or multi-behavior?

Is the intervention labeled as “teach back”? Yes/No

If no, what is the intervention called? (If Yes, put “N/a”)

Did the teach-back intervention describe the use of a framing phrase to place the burden of clear communication on the clinician rather than the person receiving the information? Yes/No

Was Clinician requests patient to repeat back information in own words described? Yes/No

Did the teach-back intervention describe the clinician evaluating what the patient (or caregiver) “taught back”? Yes/No

Did the teach-back intervention describe the clinician providing additional information or clarification if the patient/caregiver’s “teach-back” was assessed to be inadequate? Yes/No

Were there additional, optional rounds of teach-back included in the intervention? Yes/No

Are caregivers present/described? Yes/No

Did caregivers participate separately in the Teach-Back intervention in addition to the patients? Yes/No Was fidelity to the Teach-Back intervention assessed? Yes/No

If so, how?

What health condition is the Teach-Back intervention designed to address (eg, heart failure)? If not condition-specific put, “N/A”

Describe the Control (ie, usual care, waitlist control, active control etc,)

The following elements in this section are for Implementation studies relevant to KQ2 ONLY. If study does not meet KQ2 criteria, please skip.

Was implementation strategy of Mobilize site staff for implementation (eg, organize teams, identify and prepare clinical champions) used? Yes/No

Was implementation strategy of Tailor, iterate, and adapt to context (eg, promote adaptability, conduct cyclical small tests of change) used? Yes/No

Was implementation strategy of Prepare sites for implementation used? Yes/No

Was implementation strategy of Train site staff and clinicians used? Yes/No

Was implementation strategy of Provide interactive assistance and site support used? Yes/No

Was implementation strategy of Support clinician practice change used? Yes/No

Was implementation strategy of Engage patients and families used? Yes/No

Please include brief description of specific implementation strategies

Notes

## PCORI IMPLEMENTATION STRATEGIES AND DEFINITIONS

Strategy | Definition | Example
Train Staff | These strategies aim to provide health care staff, clinicians, or other partners with the knowledge, skills, and confidence to successfully deliver the evidence-based practice and to maintain this expertise in the workforce over time. These strategies specify the training methods and mode used, including how they may be tailored to different learning styles, contexts, and populations. | Conduct educational meetings
Tailor, Iterate, Adapt | Several strategies have been developed and used so that evidence-based practice efforts better fit the particular and sometimes evolving context and circumstances of the sites where they occur. These strategies are often dynamic and can be focused on the practice to be implemented or the implementation strategy. | Tailor the implementation strategy to the site
Support Practice Change | These strategies aim to support the adoption of a new practice in a particular context by enacting specific changes to roles, responsibilities, teaming behaviors, workflows, and clinical information and performance monitoring systems to support the adoption, implementation, and sustained integration of the evidence-based practice. | Clinical decision support tools
Implementation Prep | Preparatory strategies enable the diagnostic assessment of the implementation contexts to assess variation across sites with respect to implementation capacity, organizational readiness, and multilevel barriers or facilitators to evidence-based practice delivery. This data can be used to develop an implementation blueprint or plan that is informed by modeling and simulation techniques to identify strategies and resource allocation methods to mitigate barriers, leverage site-level facilitating factors, and deploy appropriate process tools to monitor the quality of blueprint delivery. | Develop an implementation blueprint
Interactive Assistance | These interactive support strategies vary by function and target (eg, individuals, inner organization setting, outer setting, implementation processes). Strategies focused on the local delivery system such as clinicians or clinics emphasize the execution of implementation processes and integration of the evidence-based practice into a setting (eg, academic detailing, internal facilitation) whereas support system strategies tend to be more centralized and aim to assist the delivery system by building capacity to deliver the practice and scale it to other settings (eg, centralized technical assistance). Strategies may also serve in a dissemination role to increase awareness, attitude, knowledge, or intention to adopt (eg, learning collaborative or sharing local knowledge). | Provide external implementation facilitation
Mobilize Staff | These strategies are used to organize, prepare and mobilize staff at implementation sites for a successful implementation of evidence-based practice. These range from establishing internal implementation leaders to setting up structures so that staff are engaged and on board with the changes to be implemented. | Organize implementation teams and team meetings
Engage Patients | These strategies may aim to actively engage clinical end users such as patients and their caregivers throughout the implementation process using participatory methods to provide meaningful feedback and contributions to key implementation decisions. Strategies in this category may also involve marketing strategies to increase demand for the evidence-based practice or behavioral strategies to engage patients to be active and informed participants in their care decisions and adherence. These range from establishing internal implementation leaders to setting up structures so that staff are engaged and on board with the changes to be implemented. | Involve end users and family members (in implementation planning)

## PEER REVIEW COMMENTS AND RESPONSES

Comment # | Reviewer # | Comment | Author Response
Are the objectives, scope, and methods for this review clearly described?
1 | 1 | Yes | Acknowledged.
2 | 2 | Yes | Acknowledged.
3 | 3 | Yes | Acknowledged.
4 | 4 | Yes | Acknowledged.
5 | 5 | Yes | Acknowledged.
6 | 6 | Yes | Acknowledged.
Is there any indication of bias in our synthesis of the evidence?
7 | 1 | No | Acknowledged.
8 | 2 | No | Acknowledged.
9 | 3 | No | Acknowledged.
10 | 4 | No | Acknowledged.
11 | 5 | No | Acknowledged.
12 | 6 | No | Acknowledged.
Are there any published or unpublished studies that we may have overlooked?
13 | 1 | No | Acknowledged.
14 | 2 | No | Acknowledged.
15 | 3 | No | Acknowledged.
16 | 4 | No | Acknowledged.
17 | 5 | No | Acknowledged.
18 | 6 | No | Acknowledged.
Additional suggestions or comments can be provided below.
19 | 1 | Pg vii- lines 5-27. As noted in my subsequent comments below, suggest changing the first key finding to read:; “We found insufficient evidence to determine the effects of teach-back on…” | We have adjusted the language in the first key finding to clarify that while we did find evidence from 8 trials related to knowledge acquisition – there was no clear pattern of effect and that there were widespread methodologic limitations. We did not use the phrase “insufficient evidence” as this has a specific GRADE meaning and could imply that there were not enough studies or not enough data which would not be accurate.
20 | 1 | pg vii l 34 – missing key concepts – suggest change to “misunderstanding key concepts and clinician recommendations” | Thank you, this has been updated accordingly.
21 | 1 | l 38. Change, “or if the patient acquired the facts of guidance as intended” to “or if the patient fully understood the information, instruction or guidance provided.” | Thank you, this has been updated accordingly.
22 | 1 | l 45 Please adjust the comment about the MISSION Act. It only requires that VA develop and administer an education program that educates Veterans about their VA health care options. VHA has expanded our response to this requirement to include educational programs, resources and activities that aim to enable and empower Veterans to stay well, prevent illness, and manage their health conditions. So, suggest it would be better to remove the reference to the MISSION Act and instead cite the VHA 2022-2025 Long Range Plan which features the strategy, “Improve outcomes and knowledge sharing by employing bi-directional communication with Veterans, their families and caregivers” , for addressing the VHA Goal 1: Maintain Trusted Longterm Relationships with Veterans. | Thank you, this has been updated accordingly.
23 | 1 | l 51 – Better to say “Teach-back involves a health care professional providing information (verbally orby demonstration), followed by a request for the recipient to fully and accurately repeat or redemonstrate this information.” | Thank you, this has been updated accordingly.
24 | 1 | pg viii-38 – re: “We found no clear pattern suggesting benefit of t-b.” You cite many concerns about methods and overall very low confidence in these findings and low strength of evidence. So, suggest rephrasing the finding to, “We found insufficient evidence regarding the effect of t-b on short-term knowledge….” | Please see response to comment #19 above.
25 | 1 | l 51-3 – may want to expand on “adherence to behaviors” beyond just citing the context and feature the specific behaviors Can cite examples such as medication taking, breastfeeding strategies, diet and physical activity | Thank you, this has been updated accordingly.
26 | 1 | pg ix Summary of Evidence Table; Consider changes in the way the findings are reported in the table for:; l 49 Patient knowledge: “There is insufficient evidence to determine the effect of the teach-back approach for conveying health information on short-term patient knowledge.”; l 57 – Patient satisfaction - “There is insufficient evidence to determine the effect of the teach-back approach for conveying health information on patient satisfaction.” | See above response to comment #19. We have changed the wording to insufficient for patient satisfaction given that there were only two studies with limited measurements of satisfaction.
27 | 1 | Pg 4 line 22 – Suggest not citing the MISSION Act, but instead cite the VHA 2022-2025 Long Range Plan Strategy, “Improve outcomes and knowledge sharing by employing bi-directional communication with Veterans, their families and caregivers.” | Thank you, this has been updated accordingly.
28 | 1 | l 26 Suggest editing to say “is considered a key strategy that health care organizations can advance organizational health literacy” | Thank you, this has been updated accordingly.
29 | 1 | l 36 Suggest a different example for intermediate outcomes (“adherence” or “self-efficacy”), given the outcomes emphasized in the findings Table 1 | Thank you, this has been updated accordingly.
30 | 1 | pg 6 l 26 – for KQ1 Proximal/intermediate outcomes – suggest listing health behaviors | Health behaviors added to eligibility criteria as one of the proximal/intermediate outcomes.
31 | 1 | pg 15 l 7-31 Though the eye surgery study (Chen, Ref 50) found a significant difference in surgical cooperation between the intervention and control group, the results from this study are not included in the discussion. Cooperation during surgery is potentially an important adherence outcome, as it has potential to reduce adverse surgical outcomes. I note there were “some concerns” with bias, though in the Bias table on page 53, there is an entry that blinding was “not possible.” However, it is possible that the surgical staff rating cooperation were not aware of the condition to which the subjects were randomized, so the observers might have been blinded (not aware of group assignment). I didn’t find any info on whether observers were blinded in the actual Chen publication (in this eye surgery study – ha ha). I wonder if it would be valuable to say more about the findings of this study in the narrative. | We have added this study as an example of objectively measured adherence and clarified in the Bias table that patients were not blinded and that it was unclear if outcome assessment was blinded or not.
32 | 1 | pg 16 l 30-33. Suggest making a comment that the self-care for heart failure teach-back intervention reported positive effects for both self-efficacy and adherence. Might also note that this was the only study I believe that included both SE and adherence outcomes. | Both Oh and Cetindemir measured both self-efficacy and adherence. We have added note of this as suggested and added outcomes from Oh on adherence to the adherence section which had been inadvertently omitted.
33 | 1 | pg 16 l 35-57 I suggest relabeling this section as “Patient Experience” and also suggest referring to these outcomes as patient experience outcomes throughout the report, rather than patient satisfaction outcomes. VHA uses the term patient experience when referring to outcomes measured by surveys of patients receiving care in VHA. These patient experience measures are based on the AHRQ’s Consumer Assessment of Healthcare Providers and Systems (CAHPS), which was used in Ref 43 (Griffey et al). The VHA version is called Survey of Healthcare Experiences of Patients (SHEP). See https://vaww.qps.med.va.gov/divisions/api/pm/shep/shepDefault.aspx for detail on SHEP. | We agree that patient satisfaction is an aspect of patient experience and have indicated this but as we defined this outcome as patient satisfaction at the outset and did identify other measures of patient experience, we have left this labeled as such. We have added clarification regarding the relationship of measured approaches to the CAHPS.
34 | | Also, Fig 2 in the supplement for Ref 44 (Dijo et al) provides the 5 “satisfaction” questions utilized in the Dijo study. 4 of the 5 items used by Dijo et al are closely aligned with the communication composite in SHEP surveys, though Dijo utilized different response categories. I don’t recognize the 5th question (“After this visit I am confident in the doctor’s ability to treat my condition”) as a CAHPS/SHEP question. It may be more accurate to say the patient experience survey was “adapted from CAHPS” rather than “author-developed” (line 54). | We added acknowledgement that these questions are similar to CAHPS as the authors did not specifically indicate the origin of this measure.
35 | 1 | Also, results presented in Table 5 in Dijo show that both the Control UC condition and the after visit instruction plus TB (AVI + TB) have very similar “satisfaction” scores, and as you note in line 57, much lower scores in the AVI alone condition compared to the AVI+TB conditions. However, the analyses conducted by Dijo did not include an analysis of this comparison. Because both of these studies have high risk of bias, and an overfall very low COE, I suggest stating there is insufficient evidence to assess the impact of TB on patient experience, rather than stating that “there is a small amount conflicting evidence.” | We have revised our language to indicate that there is insufficient evidence on patient satisfaction.
36 | 1 | Pg 20 l 15-26. I believe this must be Ref 32 (Kingbell). Consider using a graphic representation of the findings from reference of “how often teach-back was currently used in practice”, which would clearly show key differences in “always” and “never” across time points. | We have added the needed citation for Klingbeil. While we appreciate the suggestion for a figure, we decided not to add given it just for one study and would not contribute significantly to the overall synthesis.
37 | 1 | l 28-36 – Suggest providing more information about the 4 implementation strategies used by Ref 53, including the terms featured in Table 3. Suggest providing information on how the average number of T-B questions were measured. | We have added additional detail on how the average number of teach-back questions were measured. We have also added a new appendix that provides the definitions along with examples for the identified implementation strategies.
38 | 1 | l 38-42 – Was documentation of T-B the only measure used to assess adoption for Ref 29? | We have noted that a small proportion of nurses requested direction observation and findings related to these observations were noted.
39 | 1 | pg 20 l 46-49. The reference numbers are wrong. Ref 33, described in the following paragraph as the “first study” utilized direct observation, not self-report. I believe ref 34 (the “third” study) utilized self-reported T-B. | Thank you, the citations have been corrected.
40 | 1 | pg 21 l 7-9. Conviction and Confidence are 2 separate self-reported scales – as noted in Table 3, so the significant increases specified in the Table should be reported separately in the paragraph narrative here, as well as also in the “Other” section – lines 29-36. I also suggest including the specific wording of both the Conviction and Confidence Scale found in the Always Use Teach-Back Toolkit (Ref 56) - https://teachbacktraining.org/wp-content/uploads/2024/06/P_ConvictionConsistencyandConfidenceSelf-Assessment_v4.pdf. The Conviction q is worded, “On a scale from 1 to 10, how convinced are you that it is important to use teach-back (ask people to explain key information back in their own words)” The scale is 1-10 with 1 “not at all convinced” and 10 “very convinced.” The Confidence Scale wording is “On a scale from 1 to 10, how confident are you in your ability to use teach-back (ask people to explain key information back in their own words)? The scale is 1-10 with 1 “not at all confident” and 10 “very confident.” It may also be worth mentioning that the Conviction Scale is very similar to the Importance Scale, which along with the Confidence Scale, is featured in Motivational Interviewing Training – including MI clinician training programs developed by NCP. Using these 2 scales to assess clinician Importance and Confidence in using specific Veteran-centered communication skills is also featured in NCP’s Clinician Coaching Training Program. | Thank you, we have separated the conviction and confidence results into two sections and included the specific wording of these scales.
41 | 1 | Pg 23 l 8-19. When first mentioning the knowledge outcome, consider emphasizing that the methodological limitations of the studies reviewed led to a very low certainty of evidence, as noted in the Limitations section. Instead of saying “we found no clear benefit of teach-back on short-term knowledge acquisition” consider, “Though we found no clear benefit of teach-back on short-term knowledge acquisition, serious methodological limitations found across the studies reviewed led us to rate the certainty of evidence as very low.” As noted previously, I suggest saying there is insufficient evidence to determine the effect of teach-back on short-term patient knowledge. I also suggest that you add an additional last sentence in the first paragraph featuring the findings of increased observed and self-reported use of teach-back strategies by clinicians in reviewed implementation studies, with the caveat that these were observational studies and not controlled trials. | We appreciate this suggestion and have added emphasis on the methodologic limitations in this section. See prior comments about rewording of this finding.; We also added a sentence to the first paragraph of the discussion about the implementation outcomes.
42 | 1 | pg 23 l 22-56. Suggest changing the order of the 4 potential reasons why T-B is “not sufficient” to impact knowledge, as measured in the studies.(line 30) Suggest starting with effects of information complexity and the sheer volume of information delivered on patient understanding (currently 3rd reason). Might also mention other barriers to comprehension related to the use of medical jargon as well as the sheer volume of information that may be provided in a single admission or urgent care or outpatient visit. Other research has found patient understanding is enhanced when the clinicians use plain language, in small chunks, supplemented by written information and graphic illustrations. Clearly, some of the studies reviewed did not feature this important step in the patient education process. Teach-back may be most likely to enhance comprehension when paired with effective information sharing. The examples provided in lines 40+ are very illustrative of the challenges associated with information complexity and overload! However, I don’t find the statement starting on line 51 to be reflective of the findings (“It could be that the true benefit of teach back may be related to self-efficacy and adherence and not patient knowledge acquisition”). I suggest either omitting this statement or restating it to reflect what has been noted about the limited certainty of evidence about knowledge. Consider, “Despite the limited evidence found for an effect of teach-back on knowledge acquisition, results from our review indicate moderate certainty of evidence for an effect of teach-back on adherence, as well as low certainty of evidence for an effect of teach-back on self-efficacy.” Also suggest omitting the last sentence (starting with “Regardless”) as this is speculative and not reflected in the findings, which were limited by having only 1 study that featured skill demonstration as a teach-back strategy, with a non-significant outcome. | We have taken these suggestions into consideration and have reordered this section somewhat. However, we have left methodologic limitations as first on the list which we feel was driving the findings for this outcome.
43 | 1 | Pg 24 l 16 – I suggest rewording the statement that begins with, “ Yet, the benefits of teach-back compared to usual approaches to patient education may only be realized…” to instead read, “Also, the full benefits of teach-back as a component of patient education will be realized, and reflected in care outcomes, when this practice is utilized with high fidelity (i.e., intervention was delivered as intended related to dose, content, form) by a majority of clinicians, at most patient learning opportunities. Though this is a lofty goal, it is potentially achievable, and measurable. | Thank you, this has been updated as suggested.
44 | 1 | L 21-24. Suggest including reference for AHRQ’s Health Literacy Universal Precautions Toolkit – https://www.ahrq.gov/health-literacy/improve/precautions/toolkit.html. Suggested citation - Brach C, ed. AHRQ Health Literacy Universal Precautions Toolkit, 3rd Edition. Rockville, MD. Agency for Healthcare Research and Quality. AHRQ Publication No. 23-0075. March 1, 2024. See also comment below | Thank you, we added the reference to the AHRQ toolkit.
45 | 1 | L 24-25 – Suggest eliminating the statement, “How to implement teach-back across clinical setting in a consistent manner is not yet known.” The statement that follows, “Unfortunately, we were unable to draw conclusions about successful teach-back implementation methods in routine care,” along with the subsequent discussion can suffice. I strongly support the final statement of this paragraph, “In lieu of clear evidence on optimal implementation strategies to promote the use of teach-back specifically, health systems can look to existing guidance on how implementation strategies should be selected for a given setting and intervention.” Suggest adding a statement here to refer readers to the specific T-B guidance developed by AHRQ for the Health Literacy Universal Precautions Toolkit implementation guidance - https://www.ahrq.gov/healthliteracy/improve/precautions/toolkit.html. Might provide a link to the specific Teach-Back section - https://www.ahrq.gov/health-literacy/improve/precautions/tool5.html (https://www.ahrq.gov/health). The AHRQ Toolkit also contains some guidance for implementing Teach-Back in Primary Care - https://www.ahrq.gov/patient-safety/reports/engage/teachback.html (https://www.ahrq.gov/patient). | Thank you, this has been updated accordingly.
46 | 1 | Pg 24 L39-56. Thanks for this paragraph. | Acknowledged
47 | 1 | L 51: Suggest the following edits to the statement, “It is likely that a low-touch educational approach such as teach-back would be best suited to clinical contexts when the knowledge or skills conveyed are relatively focused (e.g., inhaler use, oral medication taking instructions).” I suggest “medication taking instructions” is a better example than glucose monitoring, which now goes beyond just using a meter to how to use and interpret continuous glucose monitoring data. | Thank you, we have replaced the example with medication taking instructions.
48 | 1 | I’m glad to see a mention of the VA’s Patient Centered Learning Program in the background section and we would appreciate a mention of the Patient Centered Learning program in this section as well. I respectfully suggest closing out the Clinical Context section with something like the following, “The VA’s Patient Centered Learning Program will advocate for implementing and evaluating teach-back initiatives in VA clinical settings as a key strategy for advancing VA’s efforts to become a health-literate health care organization. [For a reference for the term health literate care organization, see Brach C, Keller D, Hernandez LM, Baur C, Parker R, Dreyer B, et al. Ten attributes of health literate health care organizations. Washington, DC: Institute of Medicine; 6, 2012]. | Thank you, this has been updated as suggested.
49 | 1 | Limitations; Pg 25 L14-15 – I believe there is a typo, should read, “In addition, the identified literature did not include studies limited to populations with relevant patient-level characteristics (e.g., literacy level, health status, age) nor……” | Thank you, this has been updated accordingly.
50 | 1 | L32-36. I believe the last sentence of the paragraph should read, something like, “However, the findings from these other studies were generally consistent with our results, with the exception that the non-controlled trials showed greater benefit of teach-back on knowledge, which is consistent with acknowledged trends that observational studies often find greater benefit than controlled trials.” | Thank you, this has been updated accordingly.
51 | 1 | P25 l 40-58 - Suggest adding to the 2nd sentence to read, “First, we need to understand for which patients teach-back is most effective and impactful.” I suggest adding “impactful” because we need more research that focuses on the downstream outcomes of teach-back – e.g., adherence, health, health conditions. As noted in the discussion of findings. there were very few studies that reported changes in clinical outcomes or health care utilization. Perhaps it would be most valuable to include an additional recommendation for future research that features these “multi-level” outcomes, for example, the effect of teach-back among patients with hypertension who are being started on a new medication that includes measures of immediate (understanding the recommended medication instructions), intermediate (adherence to the instructions) and clinical and/or utilization outcomes (e.g., bp control). | Thank you, this has been updated as suggested.
52 | 1 | L 46-49 – Suggest editing the following sentence to read, “Only 1 study evaluated the effect of teach-back in a population with a suspected increased risk of having low health literacy or who might be at higher risk for misunderstanding.”; Great to see the emphasis on engaging Veteran Care Partners in the final sentences of this paragraph | Thank you, this has been updated accordingly.
53 | 1 | P 26 l 3-13 Suggest adding to the first sentence to read, “Second, we need to know in which settings and for which conditions teach-back is most effective and impactful.” I agree with the need to conduct more primary care-based research, as noted in the last couple of sentences here. I also think it is also important to mention the potential value of conducting research within the context of self-management programs, such as multi-session diabetes self-management programs, or MOVE!, VHA’s comprehensive self-management program for weight management. The design of such a trial could isolate the impact of adding a specific focus on teach-back at the end of every session vs. usual care. Outcomes could include short-term, intermediate and longer-term outcomes. A focus on the context of self-management programming also algins with the 3rd recommendation that focuses on encouraging clinical staff to reliably use teach-back over time. | We have added the term “impactful” and have added self-management as an example in the future research table.
54 | 1 | L26-27 – also heartily agree with the recommendation to conduct hybrid effectiveness-implementation study designs! NCP would love to collaborate or help “sponsor” such trials!. | Acknowledged.
55 | 1 | L 34+ I love the Table. Suggest the following:; - For Population – 1st bullet - suggest changing “differences” to “needs.” Would add a bullet to Population to feature Individuals with new diagnosed chronic diseases (e.g., hypertension, diabetes, COPD, CRF).; - For Intervention – add a bullet that features self-management and rehabilitation programs. Suggest reiterating the potential value of hybrid effectiveness-implementation trials!; - For Comparator – I don’t think “alternative” patient education approaches (there is a typo there) is a priority. i would favor more studies evaluationg educational intervention versus educational intervention + focused teach-back (e.g., the example I gave previously for adding a focus on teach-back to self-management education programs versus “usual self-management program”); - For outcomes – please add medication taking or medication adherence to the intermediate examples; - For Timing – add to long term outcomes examples (chronic condition outcomes [e.g., bp or DM control], utilization of health care services [e.g., urgent care visits, readmissions]. | The suggested changes to the future research table have been made.
56 | 1 | Pg 27 L 5-12 I have the following suggestions for edits to the Conclusion section: “Teach-back is a straightforward and low-risk health education strategy that improves patient self-efficacy and adherence to recommended health-related behaviors and self-care. Areas of uncertainty include impact on health knowledge and skill acquisition across conditions and settings and how to successfully implement and maintain routine use of teach-back, particularly in non-research clinical settings. Studies of the real-world impact of teach-back while evaluating which strategies best impact routine clinician use of teach-back could help improve the incorporation of this educational approach across clinical settings and ultimately impact meaningful patient and population outcomes” | Thank you, the conclusion section has been updated incorporating the suggested language.
57 | 2 | This is a well written evidence based synthesis examining the efficacy of teach-back to improve knowledge, adherence, and self-efficacy. Below are some suggestions to improve consistency of reporting. | Acknowledged.
58 | 2 | 1. The results should be consistently reported to reduce bias. For example, the knowledge results provides information on if there was justification for the measures and describes in detail low bias studies- but these aren’t included in the other result sections. | We appreciate this recommendation and have added an example study to each outcome section. For outcomes where we were able to conduct meta-analysis, we focus on reporting the synthesis across relevant studies rather than reporting each included study narratively.
59 | 2 | 2. Patient satisfaction only has 2 studies, yet it is included in the summary of evidence table on page ix and certainty of evidence table on page 17, as being able to be interpreted with very low certainty (same as other outcomes). it is also described on page ix without additional context to suggesting it is able to be interpreted. It is not described in the discussion or summaries/conclusions, suggesting the authors do not feel it is interpretable. Suggest taking it out of Tables on page ix and 17. I also suggest taking it out of the description on page ix (this is consistent with implementation outcomes not being individually described on page ix). | Thank you for this suggestion. The patient satisfaction outcome was identified a priori as an outcome that would be assessed using GRADE. We added additional text to the discussion and conclusion and have changed the finding summary to be “insufficient.”
60 | 2 | 3. The clinical outcomes have 7 trials, it isn’t immediately clear why a quantitative meta-analyses was not completed. . These results are also not listed in the summary of evidence table on page ix and certainty of evidence table 2 page 17. In the discussion, it is stated that this outcome should be listed as exploratory because distal clinical outcomes were only examined if there was also a more proximal outcome. If this is why a quantitative analysis was not completed, this should be more clear to the reader. For example, stating that this an exploratory outcome in the results section and either not describing the results on page ix or stating that this was exploratory because it was distal outcomes on page ix. | We have added text to the results and discussion sections to clarify that the clinical outcomes were strictly exploratory. There were not enough studies measuring the same outcome to conduct a meta-analysis.
61 | 2 | 4. There are inconsistencies in how the conclusions are written between the summary page 23 and 27 which states there was improvements and page ix which states it may improve certain outcomes | Thank you, we have rewritten and harmonized the conclusions sections between the main report and the executive summary.
62 6 | 3 | I have very few comments.; Page 5 - Table 1 - could the authors please clarify if non-student trainees (e.g., residents) were excluded or included? | Thank you, we have updated the eligibility criteria to specify that non-student trainees were included if they were conducting teach-back in the context of usual clinical care.
63 | 3 | Page 12, lines 23-26: The sentence is unclear. I do not understand what they authors are trying to convey. | We have added examples of language that places the burden on the provider and not the patient as specified by Shersher et al.
64 | 3 | Page 20: paragraphs at lines 27 and 38 should say “a QI project” | Thank you, this has been updated accordingly
65 | 3 | The point about NNT is impressive. I don’t typically think about NNT in these type of interventions. Kudos to the authors on this important finding. | Thank you, acknowledged.
66 | 4 | Key findings: double check counts of studies and separate bullet points if they are from different aims of the review that should be stated | Thank you, this has been updated as suggested above.
67 | 4 | Page viii the numbers are too confusing and without context. Are those 7 out of the 16? Why is there a reference to 5 of seven trials in a paragraph that begins by describing six trials? | Thank you, we have clarified the counts by adding context. Note that not all study data was included in a meta-analysis if it was not reported in such a way that it could be combined with other studies.
68 | 4 | Pg ix, Line 23-30. This paragraph seems to address a different. It would make this seem clearer to specify the difference. | We have added the key questions to the executive summary to identify which findings are pertinent to which question.
69 | 4 | Summary of Evidence Table: The numbers don’t seem to agree with the narrative. There are five trials discussed on page 14 (not six)? | Thank you, we have clarified that not all of the identified studies are eligible for inclusion in the meta-analysis.
70 | 4 | Page 15 line 47. “Four of the 5…” so did this make it so the Self-efficacy in “specific situations” couldn’t get include in the meta-analysis? | Thank you, see response above.
71 | 4 | Page 16. What prevented all 5 from being in the meta-analysis? | Thank you, we have clarified that some studies were not methodologically similar to the rest of the identified studies (eg, differences in outcome reporting).
72 | 5 | Executive Summary Background (page vii) Lines 42-45: Add that six Healthy People 2030 objectives are related to health literacy, including one objective specific to teach-back, as this is more specific than the overall goal. See this page for reference: https://odphp.health.gov/healthypeople/priority-areas/health-literacy-healthy-people-2030 | We have removed the language in the background of the ES about Healthy People 2030 based on other feedback.
73 | 5 | Executive Summary Background (page vii) Lines 45 and 46-Remove the sentence “Within VHA, the Mission Act of 2018 requires that VA develop and administer a program to educate Veterans about their health.” The Mission Act of 2018 is not directly tied to teach-back, rather it created the Patient Centered Learning Program who identified teach-back as a priority. | Thank you, we have adopted the language suggested by reviewer 1 (comment 22).
74 | 5 | Executive Summary Background (page vii) lines 50-52: Add the following sentence after the sentence here: “If a patient is unable to fully repeat or redemonstrate this information, the health care professional should reshare or redemonstrate the information, using easy to understand language, visual aids, and other health literacy strategies until the patient confirms understanding.” This is an important component of teach-back, to reshare or repeat information if patient understanding is unclear. | Thank you, this has been updated as suggested.
75 | 5 | Main Report Background (page 4) Lines 19-21: Add that six Healthy People 2030 objectives are related to health literacy, including one objective specific to teach-back, as this is more specific than the overall goal. See this page for reference: https://odphp.health.gov/healthypeople/priority-areas/health-literacy-healthy-people-2030 | Thank you, this has been updated accordingly.
76 | 5 | Main report Background: (page 4) Lines 26-27: It would also be great to adjust the sentence to say the following, if you agree with this recommendation: Teach-back has been identified as a strategy to promote patient and family understanding of health information, as well as a strategy to promote patient adherence and adoption of health behaviors, and is considered a method of organizational health literacy. I think some mention of teach-back as a health behavior change strategy (not just a health literacy strategy) would be relevant and appropriate. It could also be elaborated upon elsewhere in the background if you agree with the recommendation. | Thank you, this feedback has been incorporated.
77 | 5 | Main Report Background (page 4) Lines 30-31: Remove “in line with the 2018 Mission Act’s requirement that VA develop and administer a program to education Veterans about their health.” The Mission Act is relevant to how the Patient Centered Learning Program was created, but is not as relevant to the identification of teach-back as a promising approach by the Patient Centered Learning Program. So I don’t think it needs to be referenced in this report. | We have adopted the language suggested by reviewer 1 (comment 27).
78 | 5 | Main Report (page 4): Lines 31-35 Add the following sentence after the sentence here: “If a patient is unable to fully repeat or redemonstrate this information, the health care professional should reshare or redemonstrate the information, using easy to understand language, visual aids, and other health literacy strategies until the patient confirms understanding.” Similar comment as in the Executive Summary. This is an important component of teach-back, to reshare or repeat information if patient understanding is unclear. | We appreciate this suggestion. We adopted the definition from Shersher, 2021 for teach-back which did not include this step as a consistent element of the definition of teach-back. However, we have noted that this is often an additional step.
79 | 5 | Main Report Discussion (page 23) Lines 30-31. Edit to the following sentence: “Second, it is likely that teach-back is not sufficient to solely improve patient knowledge in certain settings, and may need to be coupled with other patient education strategies. This may include settings such as…” This emphasizes the role that teach-back has when coupled with other patient education strategies, and may also be a reason why it’s challenging to synthesize results specifically from teach-back. | Thank you, this has been updated to include additional reference to combined educational strategies.
80 | 5 | Main Report Discussion (page 24): Lines 51-53: Edit to the following sentence: “It is possible that such a low-touch educational approach such as teach-back would be best suited to when the knowledge or skills conveyed are relatively focused (eg, inhaler use, glucose monitoring) and may need to be combined with other patient education strategies to support patient learning preferences.” Similar comment as above, emphasizing the potential role of teach-back when combined with other patient education strategies I think is particularly beneficial. | We appreciate this suggestion. This section has been revised.
81 | 5 | Main Report Future Research (page 26) Lines 3-4 Edit to the following sentence: “Second, we need to know in which settings and for which conditions and health behaviors teach-back is most effective.” Adding “and health behaviors” here I think is important to specify that teach-back might be particularly beneficial for certain behaviors and skills required for managing certain health conditions, such as using an inhaler or taking medicine-and I think this is a bit different than just specifying which health conditions. | Thank you, this has been updated accordingly.
82 | 5 | Main Report Conclusions (page 27) Lines 9-11. Edit to the following sentence: Studies of the real-world impact of teach-back while evaluating which strategies best encourage teach-back use, and in which clinical contexts, could help improve the incorporation of this educational approach and ultimately meaningful patient outcomes. Adding “and in which clinical contexts” might be beneficial here to emphasize that more research is needed for when clinicians would meaningfully use teach-back in the context of care, as it is unrealistic to expect clinicians to use teach-back every time they provide patient education. | We have revised the conclusion with this suggestion in mind.
83 | 6 | Page VII. Line 45. Delete this sentence: “Within VHA, the Mission Act of 2018 requires that the VA develop and administer a program to educate Veterans about their health.” The legislation specifically requires education about eligibility for care, priority groups for enrollment, copayments, utilization of access standards, health insurance, and what to do if a Veteran has a complaint. The legislation is not applicable in the clinical setting explored in this review. | We have updated this section as suggested by reviewer 1 (comment 22).
84 | 6 | Page 4 – line 30. I believe this should end here: “It has also been identified by the Patient Centered Learning Program as a promising approach to promote VA organizational literacy and Veteran education.” Remove this part: “in line with the 2018 Mission Act’s requirement that VA develop and administer a program to educate Veterans about their health.” | We have adopted the language suggested by reviewer 1 (comment 27).
85 | 6 | Page 7 – line 33 – Excel should be capitalized. | Thank you, this has been updated accordingly.
86 | 6 | Page 11 – Line 35. There is an extra period. | Thank you, this has been updated accordingly.
87 | 6 | Page 26 – Lines 36-54. The indentation of the bullets is off in the table, the text starts at different spots. | Thank you, this has been updated accordingly.
88 | 6 | Page 26 – Line 6: Grammar error “While already in used in practice” | Thank you, this has been updated accordingly.