# ABBREVIATIONS TABLE

Abbreviation: Definition
A1c: Hemoglobin A1c
AHRQ: Agency for Healthcare Research and Quality
APP: Advanced practice provider
AVS+TB: After-visit summary and teach-back
CABG: Coronary artery bypass graft
CAHPS: Consumer assessment of healthcare providers and systems
COE: Certainty of evidence
CINHL: Cumulative Index to Nursing and Allied Health Literature
CVD: Cardiovascular disease
DKL: Diabetes knowledge level
EPOC: Effective Practice and Organisation of Care
ERIC: Expert recommendations for implementing change
GRADE: Grading of recommendations, assessment, development, and evaluation
LATCH: Latch, audible swallowing, type of nipple, comfort, and hold
LCSW: Licensed clinical social worker
MD: Medical doctor
NNT: Number needed to treat
PCORI: Patient-Centered Outcomes Research Institute
PI: Prediction intervals
PICOT: Patient, intervention, comparator, outcome, time
PRESS: Peer review of electronic search strategies
PROSPERO: International Prospective Register of Systematic Reviews
QI: Quality improvement
REALM-R: Rapid estimate of adult literacy in medicine – revised
RCT: Randomized controlled trial
ROB: Risk of bias
SD: Standard deviation
SMD: Standardized mean difference
TEP: Technical expert panel
VHA: Veterans Health Administration