# REFERENCES

1 Palmateer N, Hamill V, Bergenstrom A, Interventions to prevent HIV and Hepatitis C among people who inject drugs: latest evidence of effectiveness from a systematic review (2011 to 2020). Int J Drug Policy. 2022;109:103872. doi:10.1016/j.drugpo.2022.103872 36202039
2 Jones L, Pickering L, Sumnall H, McVeigh J, Bellis MA. Optimal provision of needle and syringe programmes for injecting drug users: a systematic review. Int J Drug Policy. 2010;21(5):335–342. doi:10.1016/j.drugpo.2010.02.001 20189375
3 Fisher DG, Fenaughty AM, Cagle HH, Wells RS. Needle exchange and injection drug use frequency: a randomized clinical trial. J Acquir Immune Defic Syndr 1999. 2003;33(2):199–205.
4 Hagan H, McGough JP, Thiede H, Hopkins S, Duchin J, Alexander ER. Reduced injection frequency and increased entry and retention in drug treatment associated with needle-exchange participation in Seattle drug injectors. J Subst Abuse Treat. 2000;19(3):247–252. doi:10.1016/S0740-5472(00)00104-5 11027894
5 Hartgers C, Buning EC, van Santen GW, Verster AD, Coutinho RA. The impact of the needle and syringe-exchange programme in Amsterdam on injecting risk behaviour. AIDS Lond Engl. 1989;3(9):571–576.
6 Marmor M, Shore RE, Titus S, Chen X, Des Jarlais DC. Drug injection rates and needle-exchange use in New York City, 1991–1996. J Urban Health Bull N Y Acad Med. 2000;77(3):359–368.
7 Monterroso ER, Hamburger ME, Vlahov D, Prevention of HIV infection in street-recruited injection drug users. The Collaborative Injection Drug User Study (CIDUS). J Acquir Immune Defic Syndr 1999. 2000;25(1):63–70.
8 Schoenbaum EE, Hartel DM, Gourevitch MN. Needle exchange use among a cohort of injecting drug users. AIDS. 1996;10(1):1729–1734. doi:10.1097/00002030-199612000-00018 8970694
9 Huo D, Bailey SL, Ouellet LJ. Cessation of injection drug use and change in injection frequency: The Chicago Needle Exchange Evaluation Study. Addiction. 2006;101(1):1606–1613. doi:10.1111/j.1360-0443.2006.01577.x 17034440
10 Bartholomew TS, Feaster DJ, Patel H, Forrest DW, Tookes HE. Reduction in injection risk behaviors after implementation of a syringe services program, Miami, Florida. J Subst Abuse Treat. 2021;127:108344. doi:10.1016/j.jsat.2021.108344 34134863
11 Cox GM, Lawless MC, Cassin SP, Geoghegan TW. Syringe exchanges: a public health response to problem drug use. Ir Med J. 2000;93(5):143–146.11072923
12 Donoghoe MC, Stimson GV, Dolan K, Alldritt L. Changes in HIV risk behaviour in clients of syringe-exchange schemes in England and Scotland. AIDS. 1989;3(5):267–272. doi:10.1097/00002030-198905000-00003 2504230
13 Iversen J, Wand H, Topp L, Kaldor J, Maher L. Reduction in HCV incidence among injection drug users attending needle and syringe programs in Australia: a linkage study. Am J Public Health. 2013;103(8):1436–1444. doi:10.2105/AJPH.2012.301206 23763399
14 Patel MR, Foote C, Duwve J, Reduction of injection-related risk behaviors after emergency implementation of a syringe services program during an HIV outbreak. J Acquir Immune Defic Syndr 1999. 2018;77(4):373–382. doi:10.1097/QAI.0000000000001615
15 Schechter MT, Strathdee SA, Cornelisse PG, Do needle exchange programmes increase the spread of HIV among injection drug users?: an investigation of the Vancouver outbreak. AIDS Lond Engl. 1999;13(6).
16 Vertefeuille J, Marx MA, Tun W, Huettner S, Strathdee SA, Vlahov D. Decline in self-reported high-risk injection-related behaviors among HIV-seropositive participants in the Baltimore needle exchange program. AIDS Behav. 2000;4(4):381–388. doi:10.1023/A:1026406623736
17 Vlahov D, Junge B, Brookmeyer R, Reductions in high-risk drug use behaviors among participants in the Baltimore needle exchange program. J Acquir Immune Defic Syndr Hum Retrovirology Off Publ Int Retrovirology Assoc. 1997;16(5):400–406.
18 Vogt RL, Breda MC, Des Jarlais DC, Gates S, Whiticar P. Hawaii’s statewide syringe exchange program. Am J Public Health. 1998;88(9):1403–1404.9736888
19 Turner-Bicknell T. Implementing best-practice with a local syringe service program: Needs-based syringe distribution. Public Health Nurs Boston Mass. 2021;38(1):85–92. doi:10.1111/phn.12823
20 Allen ST, Mazhnaya A, O’Rourke A, Factors associated with sterile syringe acquisition among people who inject drugs in West Virginia. Subst Use Misuse. 2021;56(1):1776–1784. doi:10.1080/10826084.2021.1954023 34311667
21 Jones AA, Park JN, Allen ST, Racial differences in overdose training, naloxone possession, and naloxone administration among clients and nonclients of a syringe services program. J Subst Abuse Treat. 2021;129:108412. doi:10.1016/j.jsat.2021.108412 34080560
22 Reed M, Wagner KD, Tran NK, Brady KA, Shinefeld J, Roth A. Prevalence and correlates of carrying naloxone among a community-based sample of opioid-using people who inject drugs. Int J Drug Policy. 2019;73:32–35. doi:10.1016/j.drugpo.2019.07.010 31336291
23 Spring C, Croxford S, Ward Z, Perceived availability and carriage of take-home naloxone and factors associated with carriage among people who inject drugs in England, Wales and Northern Ireland. Int J Drug Policy. 2022;102:103615. doi:10.1016/j.drugpo.2022.103615 35172254
24 Kim K, Oh H, Miller D, Veloso D, Lin J, McFarland W. Prevalence and disparities in opioid overdose response training among people who inject drugs, San Francisco: naloxone training among injectors in San Francisco. Int J Drug Policy. 2021;90:102778. doi:10.1016/j.drugpo.2020.102778 32507683
25 Latkin CA, Davey MA, Hua W. Needle exchange program utilization and entry into drug user treatment: is there a long-term connection in Baltimore, Maryland? Subst Use Misuse. 2006;41(1):1991–2001. doi:10.1080/10826080601026027 17162601
26 Kuo I, Brady J, Butler C, Feasibility of referring drug users from a needle exchange program into an addiction treatment program: experience with a mobile treatment van and LAAM maintenance. J Subst Abuse Treat. 2003;24(1):67–74. doi:10.1016/S0740-5472(02)00343-4 12646332
27 Strathdee SA, Celentano DD, Shah N, Needle-exchange attendance and health care utilization promote entry into detoxification. J Urban Health Bull N Y Acad Med. 1999;76(4):448–460.
28 Brooner R, Kidorf M, King V, Beilenson P, Svikis D, Vlahov D. Drug abuse treatment success among needle exchange participants. Public Health Rep Wash DC 1974. 1998;113:129–139.
29 Lewis CF, Rivera AV, Crawford ND, DeCuir J, Amesty S. Pharmacy-randomized intervention delivering HIV prevention services during the syringe sale to people who inject drugs in New York City. Drug Alcohol Depend. 2015;153:72–77. doi:10.1016/j.drugalcdep.2015.06.006 26118831
30 Cleland CM, Deren S, Fuller CM, Syringe disposal among injection drug users in Harlem and the Bronx during the New York State Expanded Syringe Access Demonstration Program. Health Educ Behav. 2007;34(2):390–403. doi:10.1177/1090198106288560 16816027
31 Cotten-Oldenburg NU, Carr P, DeBoer JM, Collison EK, Novotny G. Impact of pharmacy-based syringe access on injection practices among injecting drug users in Minnesota, 1998 to 1999: JAIDS J Acquir Immune Defic Syndr. 2001;27(2):183–192. doi:10.1097/00126334-200106010-00014 11404541
32 Bluthenthal RN, Malik MR, Grau LE, Singer M, Marshall P, Heimer R. Sterile syringe access conditions and variations in HIV risk among drug injectors in three cities. Addict Abingdon Engl. 2004;99(9):1136–1146.
33 Coffin PO, Latka MH, Latkin C, Safe syringe disposal is related to safe syringe access among HIV-positive injection drug users. AIDS Behav. 2007;11(5):652–662. doi:10.1007/s10461-006-9171-x 17053854
34 Dasgupta S, Broz D, Tanner M, Changes in reported injection behaviors following the public health response to an HIV outbreak among people who inject drugs: Indiana, 2016. AIDS Behav. 2019;23(1):3257–3266. doi:10.1007/s10461-019-02600-x 31313095
35 Khoshnood K, Blankenship KM, Pollack HA, Roan CT, Altice FL. Syringe source, use, and discard among injection-drug users in New Haven, Connecticut. AIDS Public Policy J. 2000;15(3):88–94.12189714
36 Quinn B, Chu D, Wenger L, Bluthenthal RN, Kral AH. Syringe disposal among people who inject drugs in Los Angeles: the role of sterile syringe source. Int J Drug Policy. 2014;25(5):905–910. doi:10.1016/j.drugpo.2014.05.008 24930425
37 Riley E, Kral A, Stopka T, Access to sterile syringes through San Francisco pharmacies and the association with HIV risk behavior among injection drug users. J Urban Health. 2010;87(4):534–542. doi:10.1007/s11524-010-9468-y 20526690
38 Sherman SG, Rusch M, Golub ET. Correlates of safe syringe acquisition and disposal practices among young IDUs: broadening our notion of risk. J Drug Issues. 2004;34(4):895–912. doi:10.1177/002204260403400409
39 Wood E, Kerr T, Spittal PM, An external evaluation of a peer-run “unsanctioned” syringe exchange program. J Urban Health Bull N Y Acad Med. 2003;80(3):455–464.
40 Zlotorzynska M, Weidle PJ, Paz-Bailey G, Broz D. Factors associated with obtaining sterile syringes from pharmacies among persons who inject drugs in 20 US cities. Int J Drug Policy. 2018;62:51–58. doi:10.1016/j.drugpo.2018.08.019 30359873
41 Levine H, Bartholomew TS, Rea-Wilson V, Syringe disposal among people who inject drugs before and after the implementation of a syringe services program. Drug Alcohol Depend. 2019;202:13–17. doi:10.1016/j.drugalcdep.2019.04.025 31280002
42 Tookes HE, Kral AH, Wenger LD, A comparison of syringe disposal practices among injection drug users in a city with versus a city without needle and syringe programs. Drug Alcohol Depend. 2012;123(1):255–259. doi:10.1016/j.drugalcdep.2011.12.001 22209091
43 Wenger LD, Martinez AN, Carpenter L, Geckeler D, Colfax G, Kral AH. Syringe disposal among injection drug users in San Francisco. Am J Public Health. 2011;101(3):484–486. doi:10.2105/AJPH.2009.179531 20466956
44 Broadhead RS, van Hulst Y, Heckathorn DD. The impact of a needle exchange’s closure. Public Health Rep Wash DC 1974. 1999;114(5):439–447.
45 Doherty MC, Garfein RS, Vlahov D, Discarded needles do not increase soon after the opening of a needle exchange program. Am J Epidemiol. 1997;145(8):730–737.9125999
46 Fuller CM, Ahern J, Vadnai L, Impact of increased syringe access: preliminary findings on injection drug user syringe source, disposal, and pharmacy sales in Harlem, New York. J Am Pharm Assoc 1996. 2002;42(6):S77–S82. doi:10.1331/1086-5802.42.0.S77.Fuller
47 Oliver KJ, Friedman SR, Maynard H, Magnuson L, Des Jarlais DC. Impact of a needle exchange program on potentially infectious syringes in public places. J Acquir Immune Defic Syndr. 1992;5(5):534–535.1560355
48 Cooper HL, Des Jarlais DC, Tempalski B, Bossak BH, Ross Z, Friedman SR. Drug-related arrest rates and spatial access to syringe exchange programs in New York City health districts: combined effects on the risk of injection-related infections among injectors. Health Place. 2012;18(2):218–228. doi:10.1016/j.healthplace.2011.09.005 22047790
49 Marx MA, Crape B, Brookmeyer RS, Trends in crime and the introduction of a needle exchange program. Am J Public Health. 2000;90(1):1933–1936.11111271
50 US Centers for Disease Control. SUDORS Dashboard: fatal overdose data. Published April 14, 2023. Accessed August 8, 2023. https://www.cdc.gov/drugoverdose/fatal/dashboard/index.html
51 Ahmad F, Cisewski J, Rossen L, Sutton P. Provisional Drug Overdose Death Counts. National Center for Health Statistics. Published July 6, 2023. Accessed August 8, 2023. https://www.cdc.gov/nchs/nvss/vsrr/drug-overdose-data.htm
52 Ciccarone D. The rise of illicit fentanyls, stimulants and the fourth wave of the opioid overdose crisis. Curr Opin Psychiatry. 2021;34(4):344–350. doi:10.1097/YCO.0000000000000717 33965972
53 Mattson CL, Tanz LJ, Quinn K, Kariisa M, Patel P, Davis NL. Trends and geographic patterns in drug and synthetic opioid overdose deaths — United States, 2013–2019. MMWR Morb Mortal Wkly Rep. 2021;70(6):202–207. doi:10.15585/mmwr.mm7006a4 33571180
54 Hoggatt KJ, Harris AH S, Washington DL, Williams EC. Prevalence of substance use and substance-related disorders among US Veterans Health Administration patients. Drug Alcohol Depend. 2021;225:108791. doi:10.1016/j.drugalcdep.2021.108791 34098384
55 Mackey K, Veazie S, Anderson J, Bourne D, Peterson K. Barriers and facilitators to the use of medications for opioid use disorder: a rapid review. J Gen Intern Med. 2020;35(S3):954–963. doi:10.1007/s11606-020-06257-4 33145687
56 US Centers for Disease Control. HIV Surveillance Report. Diagnoses of HIV Infection in the United States and Dependent Areas 2020. Published January 31, 2023. Accessed August 8, 2023. https://www.cdc.gov/hiv/library/reports/hiv-surveillance/vol-33/index.html
57 US Centers for Disease Control. Hepatitis C Surveillance 2020. Published September 14, 2022. Accessed August 8, 2023. https://www.cdc.gov/hepatitis/statistics/2020surveillance/hepatitis-c.htm
58 US Department of Veterans Affairs. Pain Management, Opioid Safety and Prescription Drug Monitoring Program (PMOP) - Overview. Accessed September 27, 2023. https://www.va.gov/PAINMANAGEMENT/PMOP/index.asp
59 US Department of Veterans Affairs, Assistant Under Secretary for Clinical Services. Interim Guidance on Syringe Services Programs (SSPs) in the Veterans Health Administration (VHA); 2021.
60 Bramson H, Des Jarlais DC, Arasteh K, State laws, syringe exchange, and HIV among persons who inject drugs in the United States: history and effectiveness. J Public Health Policy. 2015;36(2):212–230. doi:10.1057/jphp.2014.54 25590514
61 National Harm Reduction Coalition. Accessed August 8, 2023. https://harmreduction.org/
62 Thakarar K, Nenninger K, Agmas W. Harm reduction services to prevent and treat infectious diseases in people who use drugs. Infect Dis Clin North Am. 2020;34(3):605–620. doi:10.1016/j.idc.2020.06.013 32782104
63 Krawczyk N, Allen ST, Schneider KE, Intersecting substance use treatment and harm reduction services: exploring the characteristics and service needs of a community-based sample of people who use drugs. Harm Reduct J. 2022;19(1):95. doi:10.1186/s12954-022-00676-8 36002850
64 Behrends CN, Nugent AV, Des Jarlais DC, Frimpong JA, Perlman DC, Schackman BR. Availability of HIV and HCV on-site testing and treatment at syringe service programs in the United States. JAIDS J Acquir Immune Defic Syndr. 2018;79(2):e76–e78. doi:10.1097/QAI.0000000000001792 29985266
65 Lurie P, Drucker E. An opportunity lost: HIV infections associated with lack of a national needle-exchange programme in the USA. The Lancet. 1997;349(9052):604–608. doi:10.1016/S0140-6736(96)05439-6
66 Fernández-Viña MH, Prood NE, Herpolsheimer A, Waimberg J, Burris S. State laws governing syringe services programs and participant syringe possession, 2014–2019. Public Health Rep. 2020;135(supp 1):128S-137S. doi:10.1177/0033354920921817 32735195
67 Jones CM. Syringe services programs: an examination of legal, policy, and funding barriers in the midst of the evolving opioid crisis in the U.S. Int J Drug Policy. 2019;70:22–32. doi:10.1016/j.drugpo.2019.04.006 31059965
68 Davis C. Federal Restrictions on Funding for Syringe Services Programs. Network for Public Health Law. Accessed August 8, 2023. https://www.networkforphl.org/news-insights/federal-restrictions-on-funding-for-syringe-services-programs/
69 North America Syringe Exchange Network. NASEN Directory. Accessed December 4, 2023. https://nasen.org
70 Rife-Pennington T, Dinges E, Ho MQ. Implementing syringe services programs within the Veterans Health Administration: facility experiences and next steps. J Am Pharm Assoc. 2023;63(1):234–240. doi:10.1016/j.japh.2022.10.019
71 The White House, Executive Office of the President, Office of National Drug Control Policy. National Drug Control Strategy. 2022. https://www.whitehouse.gov/wp-content/uploads/2022/04/National-Drug-Control-2022Strategy.pdf
72 Robinson KA, Brunnhuber K, Ciliska D, Juhl CB, Christensen R, Lund H. What evidence-based research is and why is it important? J Clin Epidemiol. 2021;129:151–157. doi:10.1016/j.jclinepi.2020.07.020 32979491
73 Whiting P, Savović J, Higgins JP T, ROBIS: a new tool to assess risk of bias in systematic reviews was developed. J Clin Epidemiol. 2016;69:225–234. doi:10.1016/j.jclinepi.2015.06.005 26092286
74 Sterne JA C, Savović J, Page MJ, RoB 2: a revised tool for assessing risk of bias in randomised trials. BMJ. Published online August 28, 2019:l4898. doi:10.1136/bmj.l4898
75 Sterne JA, Hernán MA, Reeves BC, ROBINS-I: a tool for assessing risk of bias in non-randomised studies of interventions. BMJ. Published online October 12, 2016:i4919. doi:10.1136/bmj.i4919
76 Slavin RE. Best evidence synthesis: an intelligent alternative to meta-analysis. J Clin Epidemiol. 1995;48(1):9–18. doi:10.1016/0895-4356(94)00097-A 7853053
77 Berkman ND, Lohr KN, Ansari M, Grading the Strength of a Body of Evidence When Assessing Health Care Interventions for the Effective Health Care Program of the Agency for Healthcare Research and Quality: An Update. In: Methods Guide for Effectiveness and Comparative Effectiveness Reviews. AHRQ Methods for Effective Health Care. Agency for Healthcare Research and Quality (US); 2008. Accessed August 8, 2023. http://www.ncbi.nlm.nih.gov/books/NBK174881/
78 Palmateer N, Kimber J, Hickman M, Hutchinson S, Rhodes T, Goldberg D. Evidence for the effectiveness of sterile injecting equipment provision in preventing hepatitis C and human immunodeficiency virus transmission among injecting drug users: a review of reviews. Addiction. 2010;105(5):844–859. doi:10.1111/j.1360-0443.2009.02888.x 20219055
79 Shea BJ, Reeves BC, Wells G, AMSTAR 2: a critical appraisal tool for systematic reviews that include randomised or non-randomised studies of healthcare interventions, or both. BMJ. Published online September 21, 2017:j4008. doi:10.1136/bmj.j4008 28935701
80 Aspinall EJ, Nambiar D, Goldberg DJ, Are needle and syringe programmes associated with a reduction in HIV transmission among people who inject drugs: a systematic review and meta-analysis. Int J Epidemiol. 2014;43(1):235–248. doi:10.1093/ije/dyt243 24374889
81 Platt L, Minozzi S, Reed J, Needle syringe programmes and opioid substitution therapy for preventing hepatitis C transmission in people who inject drugs. Cochrane Database Syst Rev. 2017;9. doi:10.1002/14651858.CD012021.pub2
82 Gibson DR, Flynn NM, Perales D. Effectiveness of syringe exchange programs in reducing HIV risk behavior and HIV seroconversion among injecting drug users: AIDS. 2001;15(11):1329–1341. doi:10.1097/00002030-200107270-00002 11504954
83 Tilson H, Aramrattana A, Bozzette SA, Preventing HIV Infection among Injecting Drug Users in High Risk Countries: An Assessment of the Evidence. National Academies Press; 2006:11731. doi:10.17226/11731
84 Wodak A, Cooney A. Effectiveness of Sterile Needle and Syringe Programming in Reducing HIV/AIDS Among Injecting Drug Users. World Health Organization; 2004.
85 Braback M, Nilsson S, Isendahl P, Troberg K, Bradvik L, Hakansson A. Malmo Treatment Referral and Intervention Study (MATRIS)-effective referral from syringe exchange to treatment for heroin dependence: a pilot randomized controlled trial. Addiction. 2016;111(5):866–873. doi:10.1111/add.13249 26613636
86 Shah NG, Celentano DD, Vlahov D, Correlates of enrollment in methadone maintenance treatment programs differ by HIV-serostatus. AIDS Lond Engl. 2000;14(1):2035–2043.
87 Neufeld K, King V, Peirce J, Kolodner K, Brooner R, Kidorf M. A comparison of 1-year substance abuse treatment outcomes in community syringe exchange participants versus other referrals. Drug Alcohol Depend. 2008;97(1):122–129. doi:10.1016/j.drugalcdep.2008.03.026 18486360
88 Doherty MC, Junge B, Rathouz P, Garfein RS, Riley E, Vlahov D. The effect of a needle exchange program on numbers of discarded needles: a 2-year follow-up. Am J Public Health. 2000;90(6):936–939.10846512
89 Kral AH, Anderson R, Flynn NM, Bluthenthal RN. Injection risk behaviors among clients of syringe exchange programs with different syringe dispensation policies. J Acquir Immune Defic Syndr 1999. 2004;37(2):1307–1312.
90 Singer M, Himmelgreen D, Weeks MR, Radda KE, Martinez R. Changing the environment of AIDS risk: findings on syringe exchange and pharmacy sales of syringes in Hartford, CT. Med Anthropol. 1997;18(1):107–130. doi:10.1080/01459740.1997.9966152 9458670
91 Turner KM E, Hutchinson S, Vickerman P, The impact of needle and syringe provision and opiate substitution therapy on the incidence of hepatitis C virus in injecting drug users: pooling of UK evidence. Addict Abingdon Engl. 2011;106(1):1978–1988. doi:10.1111/j.1360-0443.2011.03515.x
92 Kidorf M. Challenges in motivating treatment enrollment in community syringe exchange participants. J Urban Health Bull N Y Acad Med. 2005;82(3):456–467. doi:10.1093/jurban/jti091
93 Strathdee SA, Ricketts EP, Huettner S, Facilitating entry into drug treatment among injection drug users referred from a needle exchange program: results from a community-based behavioral intervention trial. Drug Alcohol Depend. 2006;83(3):225–232. doi:10.1016/j.drugalcdep.2005.11.015 16364566
94 American Academy of Addiction Psychiatry. Clean Needle and Syringe. Accessed December 4, 2023. https://www.aaap.org/wp-content/uploads/2018/07/Clean-Needle-and-Syringe-2002-1-2018-final.pdf
95 American Bar Association. ABA Urges Federal Support for Syringe Exchange Programs. Published April 11, 2021. Accessed September 27, 2023. https://www.americanbar.org/advocacy/governmental_legislative_work/publications/governmental_affairs_periodicals/washingtonletter/2011/april/syringeexchange/
96 American Medical Association. Needle & Syringe Exchanges. Accessed September 27, 2023. https://www.ama-assn.org/topics/needle-syringe-exchanges
97 American Public Health Association. An Equitable Response to the Ongoing Opioid Crisis. Published October 26, 2021. Accessed September 27, 2023. https://www.apha.org/Policies-and-Advocacy/Public-Health-Policy-Statements/Policy-Database/2022/01/07/An-Equitable-Response-to-the-Ongoing-Opioid-Crisis
98 US Centers for Disease Control and Prevention. Summary of Information on The Safety and Effectiveness of Syringe Services Programs (SSPs). Published January 11, 2023. Accessed September 27, 2023. https://www.cdc.gov/ssp/syringe-services-programs-summary.html
99 US Centers for Disease Control and Prevention. Syringe Services Programs (SSPs). Published September 25, 2023. Accessed September 27, 2023. https://www.cdc.gov/ssp/index.html
100 European Centre for Disease Prevention and Control. ECDC and EMCDDA Technical Guidance on Prevention and Control of Infectious Diseases among People Who Inject Drugs; 2011. Accessed September 27, 2023. https://www.ecdc.europa.eu/en/publications-data/ecdc-and-emcdda-technical-guidance-prevention-and-control-infectious-diseases-0
101 UNAIDS. HIV Prevention 2025 Road Map, 2022. Accessed September 27, 2023. https://hivpreventioncoalition.unaids.org/wp-content/uploads/2023/05/JC3053_2022-HIV-Road-Map-Publication_En_v6-Final.pdf
102 World Health Organization. Guide to Starting and Managing Needle and Syringe Programmes, 2007. Accessed September 27, 2023. https://www.who.int/publications/i/item/guide-to-starting-and-managing-needle-and-syringe-programmes
103 Kariisa M, O’Donnell J, Kumar S, Mattson CL, Goldberger BA. Illicitly manufactured fentanyl–involved overdose deaths with detected xylazine — United States, January 2019–June 2022. MMWR Morb Mortal Wkly Rep. 2023;72(26):721–727. doi:10.15585/mmwr.mm7226a4 37384558
104 Assessing Ksobiech K. and improving needle exchange programs: gaps and problems in the literature. Harm Reduct J. 2004;1(1):4. doi:10.1186/1477-7517-1-4 15169543
105 Packham A. Syringe exchange programs and harm reduction: new evidence in the wake of the opioid epidemic. J Public Econ. 2022;215:104733.
106 Lambdin BH, Bluthenthal RN, Humphrey JL, LaKosky P, Prohaska S, Kral AH. ‘New evidence’ for syringe services programs? a call for rigor and skepticism. Int J Drug Policy. 2023;121:104107. doi:10.1016/j.drugpo.2023.104107 37996217
107 Bluthenthal RN, Anderson R, Flynn NM, Kral AH. Higher syringe coverage is associated with lower odds of HIV risk and does not increase unsafe syringe disposal among syringe exchange program clients. Drug Alcohol Depend. 2007;89(2):214–222. doi:10.1016/j.drugalcdep.2006.12.035 17280802