# ACKNOWLEDGMENTS

The authors are grateful to Becky Baltich Nelson, MLS, MS for literature searching, Payten Sonnen for editorial and citation management support, external peer reviewers, and the following individuals for their contributions to this project:

## Operational Partners

Operational partners are system-level stakeholders who help ensure relevance of the review topic to the VA, contribute to the development of and approve final project scope and timeframe for completion, provide feedback on the draft report, and provide consultation on strategies for dissemination of the report to the field and relevant groups.

- Jodie Trafton, PhD
  Director, VA Program Evaluation and Resource Center
  Office of Mental Health and Suicide Prevention
- Audrey Kusiak, PhD
  Scientific Program Manager, Rehabilitation Research and Development Service
  Office of Research and Development
- Dominick DePhilippis, PhD
  Deputy National Mental Health Director, Substance Use Disorders
  Office of Mental Health and Suicide Prevention
- David Ross, MD, PhD, MBI
  Director; HIV, Hepatitis, and Related Conditions Programs
  Office of Specialty Care Services