# Executive Summary

## KEY FINDINGS

▶ Despite some gaps, the evidence demonstrating the potential benefits of SSPs and relative lack of harms is sufficient to support SSP implementation when possible.
▶ SSP utilization likely lowers HIV transmission and reduces injection risk behaviors, and may lower HCV transmission, promote carrying naloxone, increase exposure to overdose education, and facilitate referral to and enrollment in treatment services. SSP use and presence in communities does not appear to increase injection frequency, unsafe syringe disposal practices, or neighborhood crime rates.
▶ Preliminary evidence suggests that combined SSP and OUD treatment programs may improve some outcomes more than either intervention alone. Coordinated or co-located SSP and OUD treatment interventions represent a promising area for future research.

Substance use-related harms including drug overdose deaths and new cases of human immunodeficiency virus (HIV) and hepatitis C (HCV) are increasing in the US. Syringe services programs (SSPs) started in the 1980s as community-based efforts to distribute sterile syringes and provide safe injection information to people who inject drugs (PWID) in response to rising HIV infection rates. SSPs are guided by harm reduction principles, which aim to mitigate the negative consequences of drug use. The term SSP broadly refers to the provision of sterile syringes and other supplies and is inclusive of any setting that provides these supplies for the intended injection of drugs. The present report is an attempt to provide an overall picture of what is known about the benefits and potential harms of SSPs, which has been an active area of research for the past 4 decades. This report was requested by the VA Offices of Mental Health and Suicide Prevention, Research and Development, and Specialty Care Services to inform VA efforts to meet the goals of the Office of National Drug Control Policy and to implement best practices for harm reduction in VHA settings.

Our search identified 399 potentially relevant articles after deduplication and title and abstract screening. We relied on results of a 2022 review of reviews to describe the effectiveness of SSPs on HIV and HCV transmission, as well as injection risk behaviors. We prioritized synthesis of 48 primary studies to evaluate the potential benefits and harms of SSPs related to injection frequency, naloxone distribution and overdose education, linkage to substance use treatment and utilization of treatment services, syringe disposal practices, and neighborhood crime rates. We also synthesized available evidence on whether outcomes vary by syringe exchange model (needs-based versus 1-for-1) or presence/absence of program components.

The 2022 review of reviews found sufficient evidence that SSPs prevent HIV transmission among PWID and tentative evidence that SSPs prevent HCV transmission. Studies of HCV prevention had less consistent results compared to studies of HIV prevention, but it is unknown whether the weaker benefit in terms of HCV prevention is primarily due to study factors (such as the ways SSP use was defined and measured in studies evaluating HCV transmission) or differences in HIV and HCV transmissibility. Additionally, the relatively recent availability of curative therapy options for HCV is likely altering the epidemiology of HCV in ways that have not yet been reflected in available evidence. The same 2022 review of reviews found sufficient evidence that SSP use reduced injection risk behaviors, an important intermediate outcome when considering that a primary aim of SSPs is to prevent infectious disease transmission.

Importantly, SSP use does not appear to increase injection frequency, unsafe disposal of syringes, or neighborhood crime rates. SSP use may be associated with increased treatment linkage and/or use of treatment services among PWID compared to no SSP use (or less use). Preliminary evidence suggests that coordinated or co-located SSPs and programs offering OUD treatment may have improved outcomes relative to either program alone, which represents a promising area for future research.

Studies of public health interventions in real-world settings often must rely on observational research methods that are intrinsically less rigorous than study designs available in clinical contexts. These methodological limitations lower the strength of available evidence for individual SSP outcomes (listed below). However, when looking across outcomes, the preponderance of evidence demonstrating the potential benefits of SSPs and relative lack of harms is more than sufficient to support SSP implementation when possible.

ES Table Summary of Evidence

Outcome | Evidence | Findings
HIV transmission | 1 RoR^1^ | SSPs likely prevent HIV transmission.
HCV transmission | 1 RoR^1^ | SSPs may prevent HCV transmission. Coordinated or co-located SSPs and programs offering OUD treatment may have improved outcomes relative to either program alone.
Injection risk behaviors | 1 RoR^1^; 1 SR^2^ | SSPs likely reduce injection risk behaviors. Use of SSPs offering needs-based or greater than 1-for-1 syringe exchange may be associated with a reduction in syringe re-use compared to use of SSPs with 1-for-1 syringe exchange polices or caps on the number of syringes dispensed.
Injection frequency | 1 RCT,^3^ 6 cohort,^4–9^ and 9 pre-post^10–18^ studies | SSP use does not appear to be associated with an increase in injection frequency.
Naloxone distribution | 1 serial cross-sectional^19^ and 4 cross-sectional^20–23^ studies | SSP use may be associated with higher rates of carrying naloxone.
Overdose education | 2 cross-sectional studies^21,24^ | SSP use may be associated with receipt of overdose education.
Linkage to SUD treatment and utilization of treatment services | 6 cohort^4,5,25–28^ and 3 pre-post^11,16,17^ studies | SSP use may be associated with increased treatment linkage and/or use of treatment services compared to no SSP use (or less use).
Syringe disposal | 1 RCT,^29^ 2 pre-post,^16,17^ 11 cross-sectional,^30–40^ and 7 ecological^41–47^ studies | SSP use and/or presence of an SSP does not appear to be associated with an increase in unsafe syringe disposal practices.
Neighborhood crime rates | 2 ecological studies^48,49^ | Presence of an SSP does not appear to be associated with an increase in neighborhood crime rates.

Abbreviations. OUD=opioid use disorder; PWID=people who inject drugs; RCT=randomized controlled trial; RoR= review of reviews; SSP=syringe services program.