# DISCUSSION

This review aimed to integrate a large and complex evidence base on the effectiveness and potential harms of SSPs to inform VHA policies and program development. Reducing harms due to substance use is a goal of the Office of National Drug Control Policy,^71^ as well as VA Offices of Mental Health and Suicide Prevention, Research and Development, and Specialty Care Services.

Findings of this review are based on more than 4 decades of research on SSPs. Despite broad changes in drug use patterns and shifts in policies related to how SSPs are permitted to operate, findings regarding the effectiveness of SSPs have been largely consistent over time. A 2022 review of reviews^1^ found sufficient evidence that SSPs prevent HIV transmission among PWID and tentative evidence that SSPs prevent HCV transmission. Studies of HCV prevention had less consistent results compared to studies of HIV prevention, but it is unknown whether the weaker benefit in terms of HCV prevention is primarily due to study factors (such as the ways SSP use was defined and measured in studies evaluating HCV transmission) or differences in HIV and HCV transmissibility. Additionally, the relatively recent availability of curative therapy options for HCV is likely altering the epidemiology of HCV in ways that have not yet been reflected in available evidence. Combined SSP and opioid agonist treatment may improve HCV prevention to a greater degree than either intervention alone.

The same 2022 review of reviews^1^ found sufficient evidence that SSP use reduced injection risk behaviors, an important intermediate outcome when considering that a primary aim of SSPs is to prevent infectious disease transmission. SSP use may also be associated with increased treatment linkage and/or use of treatment services among PWID compared to no SSP use (or less use).

SSP use does not appear to increase injection frequency among PWID, result in an increase in unsafe syringe disposal practices, or directly increase neighborhood crime rates. Authors of a 2012 ecological study^48^ of arrest trends in proximity to SSP locations in New York City noted “the spatial overlap of these two features of the risk and protective environment likely reflects their shared target population and target behaviors.” This framing underscores the point noted by several study authors that SSPs serve a segment of the PWID population with a higher baseline risk for drug-related harms, including legal system involvement. Despite this higher baseline risk, we found no evidence that SSP use further heightens risk to PWID or communities.

Studies of public health interventions in real-world settings often must rely on observational research methods that are intrinsically less rigorous than study designs available in clinical contexts. These methodological limitations lower the strength of available evidence for individual SSP outcomes (see Appendix). However, when looking across outcomes, the preponderance of evidence demonstrating the potential benefits of SSPs and relative lack of harms is more than sufficient to support SSP implementation when possible. This overall conclusion is consistent with recommendations from several public health organizations and professional societies regarding the role of SSPs in harm reduction, including statements from the CDC describing SSPs as “safe, effective, and cost-saving” (see Table 9).

Table 9 Public Health Organization and Professional Society Statements Regarding SSPs

American Academy of Addiction Psychiatry^94^ | Supports the funding and development of programs that assist people, who are injecting drug users, to have increased access to clean needles and syringes to help them eliminate all reusing and sharing of needle syringes.
American Bar Association^95^ | Expressed support in 2011 for continuation of federal funding for syringe exchange programs, which the association maintains are an effective public strategy for reducing the transmission of HIV/AIDS in the United States.
American Medical Association^96^ | The AMA strongly supports needle and syringe exchange programs as part of a wider harm reduction approach to treating substance abuse and addiction.
American Public Health Association^97^ | State and local health departments, tribal leaders and/or councils, and community agencies should implement comprehensive SSPs for people who inject drugs to mitigate the risk of blood-borne infections (HIV and HCV) at the community level.
Centers for Disease Control and Prevention^98,99^ | Nearly 30 years of research shows that comprehensive SSPs are safe, effective, and cost-saving, do not increase illegal drug use or crime, and play an important role in reducing the transmission of viral hepatitis, HIV, and other infections.
European Centre for Disease Prevention and Control and European Monitoring Centre for Drugs and Drug Addiction^100^ | 2011 guidance states that provision of, and legal access to, clean drug injection equipment, including sufficient supply of sterile needles and syringes, free of charge, as part of a combined multi-component approach implemented through harm-reduction, counseling, and treatment programs, is a key intervention component for prevention of infections among PWID.
Joint United Nations Progamme on HIV/AIDS (UNAIDS)^101^ | Given the prominence of unsafe injecting drug use due to the limited availability of needle and syringe programs in the HIV epidemics in many countries, comprehensive harm reduction services are vitally important, including in prisons and other closed settings. The services therefore should include needle and syringe programs, opioid substitution therapy and naloxone, and should address the specific needs of women who use drugs.
World Health Organization^102^ | Evidence from 20 years of research shows that needle and syringe programs prevent, control, and ultimately reduce prevalence of HIV and other blood-borne infections among injecting drug users.

Abbreviations. AMA=American Medical Association; HCV=hepatitis C virus; HIV=human immunodeficiency virus; PWID=people who inject drugs; SSP=syringe services program.

Limitations

The existing evidence base has several limitations. First, studies used different measures for SSP exposure (eg, number of visits, percent of syringe coverage, etc) and outcomes, limiting our ability to compare results across studies in some cases. Second, many studies relied on participant self-report for both SSP use and outcomes of interest. In general, participant self-report has potential for recall bias and social desirability bias. Third, observational studies have potential bias due to uncontrolled confounding. While several studies used adjusted analyses to minimize the effect of confounding variables, effect estimates could still be skewed by unmeasured confounders. Finally, even though study periods span 4 decades, most studies were conducted in urban populations and prior to the current era of substance use in which illicit fentanyl and methamphetamine use is more common. Although most findings discussed in this review are broadly applicable to a range of populations and settings, whether specific benefits of SSPs apply to all segments of PWID is unclear.

## FUTURE RESEARCH

Despite some evidence gaps, additional research on existing SSP models may not be of practical value to health care policymakers given that available evidence is sufficient to support SSP implementation when possible. However, given that drug use patterns are constantly evolving and often regionally specific, future research on strategies to improve the responsiveness of SSPs to shifts in drug use patterns would be informative. For example, studies included in this review were largely conducted prior to the emergence of xylazine as a more common component of the illicit drug supply.^103^ Future research could examine best practices to provide PWID with tools and information needed to reduce harms associated with xylazine exposure.

We note that studying SSPs presents several methodological challenges. One challenge is how to compare findings across SSPs, which may have inconsistent approaches to defining and measuring outcomes.^104^ Another challenge is integrating data sources to derive valid and meaningful conclusions. A recent study using administrative data to evaluate links between SSPs openings and drug-related health outcomes illustrates this point.^105^ In this study, the author concluded that SSPs increase rates of opioid-related mortality based on an analysis of county-level data on SSP openings and overdose fatalities. However, this analysis has been criticized for assuming that because an association exists between an exposure and an outcome at the population level, it exists at the individual level (a concept known as ecological fallacy).^106^ Future researchers have the benefit of learning from decades of research on SSPs and should take care to avoid known causes of data misinterpretation.

## CONCLUSIONS

SSP utilization likely results in lower HIV transmission and reduced injection risk behaviors, and may result in lower HCV transmission, promote carrying naloxone, increase exposure to overdose education, and facilitate referral to and enrollment in treatment services. SSP use and presence in communities does not appear to increase injection frequency, unsafe syringe disposal practices, or neighborhood crime rates. Combined SSP and opioid agonist treatment may improve HCV prevention to a greater degree than either intervention alone. The effectiveness of other SSP program components or practices has been less frequently studied and evidence is insufficient to draw conclusions regarding best practices. Overall, when viewed as a harm reduction intervention, SSPs appear to offer a range of potential benefits without evidence suggesting that SSPs introduce harms or other unintended consequences.