# METHODS

## REGISTRATION AND REVIEW

A preregistered protocol for this review can be found on the PROSPERO international prospective register of systematic reviews (CRD42023438525 (https://www.crd.york.ac.uk/prospero/display_record.php?RecordID=438525)).

## KEY QUESTIONS AND ELIGIBILITY CRITERIA

The following key questions were the focus of this review:

Key Question 1 | What are the benefits and harms of syringe services programs?
Key Question 1a | Do benefits and harms of syringe services programs vary by exchange model (needs-based vs 1-for-1) or presence/absence of program components?

Study eligibility criteria are shown in the table below. Systematic reviews were required to meet predefined methodological criteria established by the AHRQ Evidence-based Practice Program^72^ to merit inclusion: 1) have an explicit and adequate search, 2) apply predefined eligibility criteria to select studies, 3) conduct risk of bias assessment for included studies, and 4) present a synthesis of results.

Population | Adults at risk for substance use-related harms.
Intervention | Syringe services programs. The primary intervention should be dispensing of sterile syringes, but programs may also include other components such as naloxone distribution, infectious disease testing, education on overdose prevention, safer injection practices, and/or infectious disease prevention, and/or referral to treatment and/or prevention services. The efficacy of these components as standalone interventions will not be evaluated.
Comparator | Any comparator or no comparator (ie, pre-post studies).
Outcomes | HIV/HCV prevalence or incidence, injection risk behaviors (sharing, borrowing, lending, reuse, or unsafe disposal of syringes); amount, speed, or frequency of injection drug use; naloxone distribution/use, knowledge of overdose risk; linkage to treatment for substance use disorder(s), HIV/HCV, HIV pre-exposure prophylaxis, or other medical needs; utilization of referred services; neighborhood crime rates or property values.
Study Design | Any, but we may prioritize studies using a best-evidence approach. Existing systematic reviews may be included to address some outcomes.

We did not examine primary studies for a given outcome when we identified a recent, rigorously conducted systematic review that included that outcome. This was the case for the outcomes of HIV/HCV prevalence and incidence and injection risk behaviors, which were covered in a recent review of reviews.^1^ Similarly, we identified a 2010 systematic review^2^ comparing SSP models and therefore restricted inclusion of primary studies relevant to Key Question 1a to more recent studies not included in that review.

## SEARCHING AND SCREENING

To identify articles relevant to the key questions, a research librarian searched Ovid MEDLINE, CINAHL, PsycINFO, and the Cochrane Database of Systematic Reviews through March 2023 using terms for syringe services programs (see Appendix for complete search strategies). Additional citations were identified from grey literature searches and hand-searching reference lists of included studies. The Cochrane Central Register of Controlled Trials was searched for underway studies. English-language titles, abstracts, and full-text articles were independently reviewed by 2 investigators, and disagreements were resolved by consensus.

## DATA ABSTRACTION AND RISK OF BIAS ASSESSMENT

Effect information and population, intervention, and comparator characteristics were abstracted from all included studies. The internal validity (risk of bias) of each study was rated using the Cochrane risk of bias tools for systematic reviews,^73^ randomized controlled trials,^74^ and nonrandomized comparison studies.^75^ We did not assess risk of bias of cross-sectional studies individually. All data abstraction and internal validity ratings were first completed by 1 investigator and then checked by another; disagreements were resolved by consensus or discussion with a third investigator (see Appendix for risk of bias ratings).

## SYNTHESIS

We synthesized studies narratively using a “best evidence” approach, meaning that we focused on the studies most germane to our Key Questions and of the highest methodological quality.^76^ We organized findings by outcome. Because we identified a recent, rigorously conducted review of reviews^1^ on HIV/HCV prevalence and incidence and injection risk behaviors, we relied on syntheses from this review for these outcomes. For included primary studies, we prioritized evidence from longitudinal studies when available.

### Strength of Evidence

After synthesizing available evidence, we rated the strength of evidence for each Key Question 1 outcome based on the methodology and risks of bias of available studies, the consistency and certainty of findings, and the directness of outcomes (whether reported outcomes are relevant to patients and providers).^77^ For the outcomes of HIV/HCV prevalence and incidence and injection risk behaviors, we report the strength of evidence conclusions from the review of reviews described above.^1^ For other outcomes, we applied the following general algorithm: high strength evidence consisted of multiple, large studies with low risk of bias, consistent and precise findings, and clinically relevant outcomes; moderate strength evidence consisted of multiple studies with low to unclear risk of bias, consistent and precise findings, and clinically relevant outcomes; low strength evidence consisted of multiple small or moderate-size studies, with unclear to high risk of bias, and inconsistent or imprecise findings; and insufficient evidence consisted of a single study or several small studies with an unclear or high risk of bias or no available studies.