# BACKGROUND

The US Centers for Disease Control and Prevention (CDC) predicts that the total number of drug overdose deaths in the 12-month period that ended in February 2023 will be nearly 110,000.^50,51^ While the increase in drug-related overdose deaths in the early 2000s was first attributed to prescription opioids and later to heroin use, the current trend of drug-related deaths is attributed to use of illicit synthetic opioids (eg, fentanyl and fentanyl analogs) as well as stimulants (eg, methamphetamine and cocaine) and exposure to these drugs in combination.^52^ From 2013 to 2019, the synthetic opioid-involved death rate increased by 1,040% and the stimulant-involved death rate increased by 317%.^53^

The extent to which US Veterans use substances with high risk of overdose has not been well studied,^54^ but deaths related to opioids have mirrored the rise seen in the general population.^55^ Other substance use-related harms, such as the transmission of bloodborne pathogens via nonsterile syringes or other drug injection supplies, have also been increasing alongside drug overdose deaths. In 2014, rates of HIV infection in the US began to increase among persons who inject drugs for the first time in 2 decades.^56^ Between 2013 and 2020, the incidence of acute hepatitis C (HCV) infection doubled.^57^ In response to these trends, VHA has implemented several initiatives to reduce substance use-related harms, including expanding access to medications to treat opioid use disorder (OUD), providing naloxone rescue kits to Veterans at risk of overdose, and developing guidance for VHA health care facilities to develop syringe services programs (SSPs) to provide sterile syringes and other supplies.^58,59^

SSPs, which have also been referred to as needle exchanges, were first implemented in European countries and Australia in the 1980s as community-based efforts to distribute sterile syringes and provide safe injection information to people who inject drugs (PWID) in response to rising HIV infection rates.^60^ These programs are guided by the principles of harm reduction, which has been defined as “a set of practical strategies and ideas aimed at reducing negative consequences associated with drug use.”^61,62^ The term SSP broadly refers to the provision of sterile syringes and other supplies and is inclusive of any setting that provides these supplies for the intended injection of drugs (including fixed locations, mobile units, and pharmacies).^62^

SSPs can vary widely in terms of their delivery models as well as the types and extent of additional health care services they provide.^63^ SSPs with comprehensive services may offer naloxone and overdose education, fentanyl test strips, testing for infectious disease, vaccinations, linkages to addiction treatment, and (less commonly) medications for OUD.^63,64^ These services are sometimes referred to collectively as wraparound services to emphasize that they are in addition to the core service of providing sterile syringes and supplies. In some cases, SSPs exclusively offering injection supplies may distribute these supplies by mail-order or through pharmacies.

In the US, public support for SSPs has varied regionally and over time. A variety of concerns about SSPs have emerged over the past several decades, including that SSPs promote or facilitate drug use, increase the frequency of injection drug use, attract PWID to communities where SSPs are located, risk public health due to unsafe syringe disposal, increase neighborhood crime, and divert funding away from addiction treatment.^62,65^ Starting in the 1980s, many states prohibited SSPs or passed laws criminalizing the possession and distribution of syringes for purposes of illicit drug use, and the federal government previously implemented a near-total ban on the use of federal funds to support SSPs.^65^ Whether SSPs are allowed to provide PWID with syringes based on need, rather than via 1-for-1 exchange, has also been a source of controversy with rules varying by state.^66^

While many restrictions were gradually rescinded starting in 2015 in response to increasing HIV and HCV infections in rural areas, an inconsistent legal framework and relative lack of public funding has limited the spread of SSPs in the US.^67,68^ According to the North American Syringe Exchange Network (NASEN) directory of SSPs^69^ (which relies on voluntary information sharing and is not a comprehensive list), the US currently has approximately 500 SSPs unevenly distributed across the country. For example, California has 58 SSPs and Kentucky has 45 listed on the NASEN website, while Kansas, Mississippi, Nebraska, South Dakota, and Wyoming have none.

VA currently offers SSPs in several locations including Danville, IL, Orlando, FL, and San Francisco, CA.^70^ The number of programs is expected to increase in response to recommendations from VHA leadership that medical centers develop SSPs or otherwise ensure Veterans enrolled in VHA care have access to SSPs where not prohibited by state, county, or local law. Through VHA initiatives including the Pain Management, Opioid Safety and Prescription Drug Monitoring Program (PMOP),^58^ VA facilitates have received funding and other supports to develop local SSPs.

Important changes in substance use trends, approaches to substance use prevention and treatment, public awareness of substance use harms, and legal and regulatory environments have occurred over the past 4 decades. Moreover, epidemiological features of HIV and HCV infection, approaches to prevention, and options for treatment of these diseases have evolved over time. A result of these changes and developments is a large and complex evidence base on SSPs. The present report is an attempt to provide an overall picture of what is known about the benefits and potential harms of SSPs. This report was requested by the VA Offices of Mental Health and Suicide Prevention, Research and Development, and Specialty Care Services to inform VA efforts to meet the goals of the Office of National Drug Control Policy^71^ and to implement best practices for harm reduction in VHA settings.