# ABBREVIATIONS TABLE

AHRQ: Agency for Healthcare Research and Quality
AIDS: Acquired immunodeficiency syndrome
CDC: Centers for Disease Control and Prevention
Cl: Confidence interval
HCV: Hepatitis C virus
HIV: Human immunodeficiency virus
IDU: Injection drug use
IRB: Injection risk behavior
KQ: Key question
OAT: Opioid agonist therapy
OR: Odds ratio
OUD: Opioid use disorder
PWID: People who inject drugs
RCT: Randomized controlled trial
RoR: Review of reviews
RR: Risk ratio
SSP: Syringe services program
SR: Systematic review
SUD: Substance use disorder
US: United States
VA: Department of Veterans Affairs
VHA: Veterans Health Administration
WHO: World Health Organization