# REFERENCES

1 U.S. Department of Veterans Affairs, Office of Mental Health and Suicide Prevention. National Veteran Suicide Prevention Annual Report In:2020.
2 U.S. Department of Veterans Affairs. National Strategy for Preventing Veteran Suicide 2018–2028. 2018. https://www.mentalhealth.va.gov/suicide_prevention/docs/Office-of-Mental-Health-and-Suicide-Prevention-National-Strategy-for-Preventing-Veterans-Suicide.pdf.
3 Centers for Disease Control and Prevention. The Social-Ecological Model: A Framework for Prevention. Published 2021. Updated January 28, 2021. Accessed June 07, 2021.
4 Hayden JA, van der Windt DA, Cartwright JL, Cote P, Bombardier C. Assessing bias in studies of prognostic factors. Ann Intern Med. 2013;158(4):280–286.23420236
5 Cramer RJ, Kapusta ND. A social-ecological framework of theory, assessment, and prevention of suicide. Frontiers in psychology. 2017;8:1756.29062296
6 Bernecker SL, Zuromski KL, Gutierrez PM, . Predicting suicide attempts among soldiers who deny suicidal ideation in the Army Study to Assess Risk and Resilience in Servicemembers (Army STARRS). Behav Res Ther. 2019;120:103350.30598236
7 Bohnert KM, Ilgen MA, McCarthy JF, Ignacio RV, Blow FC, Katz IR. Tobacco use disorder and the risk of suicide mortality. Addiction. 2014;109(1):155–162.24134689
8 Chu C, Zuromski KL, Bernecker SL, . A test of the interpersonal theory of suicide in a large, representative, retrospective and prospective study: Results from the Army Study to Assess Risk and Resilience in Servicemembers (Army STARRS). Behav Res Ther. 2020;132:103688.32731055
9 LeardMann CA, Powell TM, Smith TC, . Risk factors associated with suicide in current and former US military personnel. JAMA. 2013;310(5):496–506.23925620
10 Naifeh JA, Nock MK, Ursano RJ, . Neurocognitive Function and Suicide in U.S. Army Soldiers. Suicide Life Threat Behav. 2017;47(5):589–602.27801502
11 Phillips CJ, LeardMann CA, Vyas KJ, Crum-Cianflone NF, White MR. Risk Factors Associated With Suicide Completions Among US Enlisted Marines. Am J Epidemiol. 2017;186(6):668–678.28595355
12 Bullman T, Schneiderman A, Bossarte R. Suicide Risk by Unit Component among Veterans Who Served in Iraq or Afghanistan. Arch Suicide Res. 2018;22(1):1–10.28281890
13 Dobscha SK, Denneson LM, Kovas AE, . Correlates of suicide among veterans treated in primary care: case-control study of a nationally representative sample. J Gen Intern Med. 2014;29 Suppl 4(4):853–860.25355088
14 Doran N, De Peralta S, Depp C, . The Validity of a Brief Risk Assessment Tool for Predicting Suicidal Behavior in Veterans Utilizing VHA Mental Health Care. Suicide Life Threat Behav. 2016;46(4):471–485.26822821
15 Finley EP, Bollinger M, Noel PH, . A national cohort study of the association between the polytrauma clinical triad and suicide-related behavior among US Veterans who served in Iraq and Afghanistan. Am J Public Health. 2015;105(2):380–387.25033126
16 Goodin CA, Prendergast DM, Pruitt LD, . Financial hardship and risk of suicide among U.S. Army personnel. Psychol Serv. 2019;16(2):286–292.30359074
17 Griffith J. A Description of Suicides in the Army National Guard During 2007-2014 and Associated Risk Factors. Suicide Life Threat Behav. 2017;47(3):266–281.27388140
18 Hyman J, Ireland R, Frost L, Cottrell L. Suicide incidence and risk factors in an active duty US military population. Am J Public Health. 2012;102 Suppl 1(Suppl 1):S138–146.22390588
19 Kang HK, Bullman TA, Smolenski DJ, Skopp NA, Gahm GA, Reger MA. Suicide risk among 1.3 million veterans who were on active duty during the Iraq and Afghanistan wars. Ann Epidemiol. 2015;25(2):96–100.25533155
20 Kimerling R, Makin-Byrd K, Louzon S, Ignacio RV, McCarthy JF. Military Sexual Trauma and Suicide Mortality. Am J Prev Med. 2016;50(6):684–691.26699249
21 Rosellini AJ, Street AE, Ursano RJ, . Sexual Assault Victimization and Mental Health Treatment, Suicide Attempts, and Career Outcomes Among Women in the US Army. Am J Public Health. 2017;107(5):732–739.28323466
22 Skopp NA, Zhang Y, Smolenski DJ, Reger MA. Risk factors for self-directed violence in US Soldiers: A case-control study. Psychiatry Res. 2016;245:194–199.27544785
23 Ursano RJ, Kessler RC, Naifeh JA, . Risk Factors Associated With Attempted Suicide Among US Army Soldiers Without a History of Mental Health Diagnosis. JAMA Psychiatry. 2018;75(10):1022–1032.30167650
24 Ursano RJ, Kessler RC, Naifeh JA, . Associations of Time-Related Deployment Variables With Risk of Suicide Attempt Among Soldiers: Results From the Army Study to Assess Risk and Resilience in Servicemembers (Army STARRS). JAMA Psychiatry. 2018;75(6):596–604.29710270
25 Ursano RJ, Naifeh JA, Kessler RC, . Nonfatal Suicidal Behaviors in the Administrative Records of Activated U.S. Army National Guard and Army Reserve Soldiers, 2004-2009. Psychiatry. 2018;81(2):173–192.30028239
26 Ursano RJ, Stein MB, Herberman Mash HB, . Documented family violence and risk of suicide attempt among U.S. Army soldiers. Psychiatry Res. 2018;262:575–582.28965813
27 Palframan KM, Blue-Howells J, Clark SC, McCarthy JF. Veterans Justice Programs: Assessing Population Risks for Suicide Deaths and Attempts. Suicide Life Threat Behav. 2020;50(4):792–804.32147866
28 Shen YC, Cunha JM, Williams TV. Time-varying associations of suicide with deployments, mental health conditions, and stressful life events among current and former US military personnel: a retrospective multivariate analysis. The Lancet Psychiatry. 2016;3(11):1039–1048.27697514
29 Smith EG, Austin KL, Kim HM, . Associations between lithium and suicide and nonsuicide death among veterans health administration patients. Pharmacoepidemiology and Drug Safety. 2015;24(SUPPL. 1):344–345.
30 Cusack M, Montgomery AE, Cashy J, Dichter M, Byrne T, Blosnich JR. Examining veteran housing instability and mortality by homicide, suicide, and unintentional injury. Journal of Social Distress and Homelessness. 2020:1–7.
31 Barth SK, Kang HK, Bullman T. All-Cause Mortality Among US Veterans of the Persian Gulf War: 13-Year Follow-up. Public Health Rep. 2016;131(6):822–830.28123229
32 Ursano RJ, Kessler RC, Naifeh JA, . Frequency of Improvised Explosive Devices and Suicide Attempts in the U.S. Army. Mil Med. 2017;182(3):e1697–e1703.28290945
33 Ursano RJ, Kessler RC, Naifeh JA, . Risk of Suicide Attempt Among Soldiers in Army Units With a History of Suicide Attempts. JAMA Psychiatry. 2017;74(9):924–931.28746705
34 Smith TC, Millennium Cohort Study T. The US Department of Defense Millennium Cohort Study: career span and beyond longitudinal follow-up. J Occup Environ Med. 2009;51(10):1193–1201.19786902
35 Louzon SA, Bossarte R, McCarthy JF, Katz IR. Does Suicidal Ideation as Measured by the PHQ-9 Predict Suicide Among VA Patients? Psychiatr Serv. 2016;67(5):517–522.26766757
36 Ilgen MA, McCarthy JF, Ignacio RV, . Psychopathology, Iraq and Afghanistan service, and suicide among Veterans Health Administration patients. J Consult Clin Psychol. 2012;80(3):323–330.22545742
37 Haney EM ONM, Carson S, Low A, Peterson K, Denneson LM, Oleksiewicz C, and Kansagara D. Suicide Risk Factors and Risk Assessment Tools: A Systematic Review. 2012.
38 Nelson HD, Denneson LM, Low AR, . Suicide Risk Assessment and Prevention: A Systematic Review Focusing on Veterans. Psychiatr Serv. 2017;68(10):1003–1015.28617209
39 Sultan S LE, Gustavson A, Sayer N, Murdoch M, MacDonald R, McKenzie L, Ullman K, Venables N, Wilt T. Population and community-based interventions to prevent suicide: a systematic review. Washington, DC Evidence Synthesis Program, Health Services Research and Development Service, Office of Research and Development, Department of Veterans Affairs 2021. https://www.hsrd.research.va.gov/publications/esp/reports.cfm.
40 Miake-Lye IM, Hempel S, Shanman R, Shekelle PG. What is an evidence map? A systematic review of published evidence maps and their definitions, methods, and products. Syst Rev. 2016;5:28.26864942
41 Barry LC, Steffens DC, Covinsky KE, Conwell Y, Li Y, Byers AL. Increased Risk of Suicide Attempts and Unintended Death Among Those Transitioning From Prison to Community in Later Life. Am J Geriatr Psychiatry. 2018;26(11):1165–1174.30146371
42 Bohnert KM, Ilgen MA, Louzon S, McCarthy JF, Katz IR. Substance use disorders and the risk of suicide mortality among men and women in the US Veterans Health Administration. Addiction. 2017;112(7):1193–1201.28301070
43 Cooper SA, Szymanski BR, Bohnert KM, Sripada RK, McCarthy JF. Association Between Positive Results on the Primary Care-Posttraumatic Stress Disorder Screen and Suicide Mortality Among US Veterans. JAMA Netw Open. 2020;3(9):e2015707.32880649
44 Lynch KE, Gatsby E, Viernes B, . Evaluation of Suicide Mortality Among Sexual Minority US Veterans From 2000 to 2017. JAMA Netw Open. 2020;3(12):e2031357.33369662
45 Reger MA, Smolenski DJ, Skopp NA, . Risk of Suicide Among US Military Service Members Following Operation Enduring Freedom or Operation Iraqi Freedom Deployment and Separation From the US Military. JAMA Psychiatry. 2015;72(6):561–569.25830941
46 Shiner B, Peltzman T, Cornelius SL, Gui J, Forehand J, Watts BV. Recent trends in the rural-urban suicide disparity among veterans using VA health care. J Behav Med. 2020.
47 Trofimovich L, Reger MA, Luxton DD, Oetjen-Gerdes LA. Suicide risk by military occupation in the DoD active component population. Suicide Life Threat Behav. 2013;43(3):274–278.23347281
48 Ursano RJ, Kessler RC, Naifeh JA, . Suicide attempts in U.S. Army combat arms, special forces and combat medics. BMC Psychiatry. 2017;17(1):194.28545424
49 Bishop TM, Walsh PG, Ashrafioun L, Lavigne JE, Pigeon WR. Sleep, suicide behaviors, and the protective role of sleep medicine. Sleep Med. 2020;66:264–270.31727433
50 Blow FC, Bohnert AS, Ilgen MA, . Suicide mortality among patients treated by the Veterans Health Administration from 2000 to 2007. Am J Public Health. 2012;102 Suppl 1:S98–104.22390612
51 Bullman T, Schneiderman A. Suicide Risk Among US Peacekeepers Serving in the Bosnia and Kosovo Theater, 1996-2002. Am J Epidemiol. 2019;188(10):1768–1773.31145431
52 Conner KR, Bohnert AS, McCarthy JF, . Mental disorder comorbidity and suicide among 2.96 million men receiving care in the Veterans Health Administration health system. J Abnorm Psychol. 2013;122(1):256–263.23088376
53 Dempsey CL, Benedek DM, Zuromski KL, . Association of Firearm Ownership, Use, Accessibility, and Storage Practices With Suicide Risk Among US Army Soldiers. JAMA Netw Open. 2019;2(6):e195383.31173124
54 Hoffmire CA, Kemp JE, Bossarte RM. Changes in Suicide Mortality for Veterans and Nonveterans by Gender and History of VHA Service Use, 2000-2010. Psychiatr Serv. 2015;66(9):959–965.25930036
55 Hostetter TA, Hoffmire CA, Forster JE, Adams RS, Stearns-Yoder KA, Brenner LA. Suicide and Traumatic Brain Injury Among Individuals Seeking Veterans Health Administration Services Between Fiscal Years 2006 and 2015. J Head Trauma Rehabil. 2019;34(5):E1–E9.
56 Ilgen MA, Kleinberg F, Ignacio RV, . Noncancer pain conditions and risk of suicide. JAMA Psychiatry. 2013;70(7):692–697.23699975
57 Katz IR, McCarthy JF, Ignacio RV, Kemp J. Suicide among veterans in 16 states, 2005 to 2008: comparisons between utilizers and nonutilizers of Veterans Health Administration (VHA) services based on data from the National Death Index, the National Violent Death Reporting System, and VHA administrative records. Am J Public Health. 2012;102 Suppl 1:S105–110.22390582
58 Martz E, Jelleberg C, Dougherty DD, Wolters C, Schneiderman A. Tinnitus, Depression, Anxiety, and Suicide in Recent Veterans: A Retrospective Analysis. Ear Hear. 2018;39(6):1046–1056.29624539
59 McCarthy JF, Ilgen MA, Austin K, Blow FC, Katz IR. Associations between body mass index and suicide in the veterans affairs health system. Obesity (Silver Spring). 2014;22(1):269–276.23512622
60 Ravindran C, Morley SW, Stephens BM, Stanley IH, Reger MA. Association of Suicide Risk With Transition to Civilian Life Among US Military Service Members. JAMA Netw Open. 2020;3(9):e2016261.32915235
61 Ribeiro JD, Gutierrez PM, Joiner TE, . Health care contact and suicide risk documentation prior to suicide death: Results from the Army Study to Assess Risk and Resilience in Servicemembers (Army STARRS). J Consult Clin Psychol. 2017;85(4):403–408.28333538
62 Ryan AT, Ghahramanlou-Holloway M, Wilcox HC, Umhau JC, Deuster PA. Mental Health Care Utilization and Psychiatric Diagnoses in a Sample of Military Suicide Decedents and Living Matched Controls. J Nerv Ment Dis. 2020;208(9):646–653.32502074
63 Schinka JA, Bossarte RM, Curtiss G, Lapcevic WA, Casey RJ. Increased Mortality Among Older Veterans Admitted to VA Homelessness Programs. Psychiatr Serv. 2016;67(4):465–468.26620292
64 Schinka JA, Leventhal KC, Lapcevic WA, Casey R. Mortality and Cause of Death in Younger Homeless Veterans. Public Health Rep. 2018;133(2):177–181.29420922
65 Ursano RJ, Kessler RC, Stein MB, . Suicide Attempts in the US Army During the Wars in Afghanistan and Iraq, 2004 to 2009. JAMA Psychiatry. 2015;72(9):917–926.26154106
66 Ursano RJ, Kessler RC, Stein MB, . Risk Factors, Methods, and Timing of Suicide Attempts Among US Army Soldiers. JAMA Psychiatry. 2016;73(7):741–749.27224848
67 Alexander CL, Reger MA, Smolenski DJ, Fullerton NR. Comparing U.S. Army suicide cases to a control sample: initial data and methodological lessons. Mil Med. 2014;179(10):1062–1066.25269121
68 Black SA, Gallaway MS, Bell MR, Ritchie EC. Prevalence and risk factors associated with suicides of Army soldiers 2001–2009. Military Psychology. 2011;23(4):433–451.
69 Gradus JL, Shipherd JC, Suvak MK, Giasson HL, Miller M. Suicide attempts and suicide among Marines: a decade of follow-up. Suicide Life Threat Behav. 2013;43(1):39–49.23082753
70 McCarthy MS, Hoffmire C, Brenner LA, Nazem S. Sleep and timing of death by suicide among U.S. Veterans 2006-2015: analysis of the American Time Use Survey and the National Violent Death Reporting System. Sleep. 2019;42(8):1–8.
71 Nock MK, Dempsey CL, Aliaga PA, . Psychological autopsy study comparing suicide decedents, suicide ideators, and propensity score matched controls: results from the study to assess risk and resilience in service members (Army STARRS). Psychol Med. 2017;47(15):2663–2674.28502265
72 Reger MA, Smolenski DJ, Skopp NA, . Suicide Risk Among Wounded U.S. Service Members. Suicide Life Threat Behav. 2017;47(2):242–247.27492873
73 Thomsen CJ, Stander VA, McWhorter SK, Rabenhorst MM, Milner JS. Effects of combat deployment on risky and self-destructive behavior among active duty military personnel. J Psychiatr Res. 2011;45(10):1321–1331.21549392
74 Zuromski KL, Dempsey CL, Ng THH, . Utilization of and barriers to treatment among suicide decedents: Results from the Army Study to Assess Risk and Resilience Among Servicemembers (Army STARRS). J Consult Clin Psychol. 2019;87(8):671–683.31008631