# ACKNOWLEDGMENTS

This topic was developed in response to a nomination by VA Health Services Research & Development (HSR&D) Office for an evidence review on the risk and protective factors for suicide across socioecological (SE) levels of risk. The scope was further developed with input from the topic nominators (ie, Operational Partners), the ESP Coordinating Center, the review team, and the technical expert panel (TEP).

In designing the study questions and methodology at the outset of this report, the ESP consulted several technical and content experts. Broad expertise and perspectives were sought. Divergent and conflicting opinions are common and perceived as healthy scientific discourse that results in a thoughtful, relevant systematic review. Therefore, in the end, study questions, design, methodologic approaches, and/or conclusions do not necessarily represent the views of individual technical and content experts.

The authors gratefully acknowledge the following individuals for their contributions to this project:

## Operational Partners

Operational partners are system-level stakeholders who have requested the report to inform decision-making. They recommend TEP participants; assure VA relevance; help develop and approve final project scope and timeframe for completion; provide feedback on draft report; and provide consultation on strategies for dissemination of the report to field and relevant groups.

- Robert O’Brien, PhD
  Scientific Program Manager
  VA HSR&D
- Lauren Denneson, PhD
  Representative of VA HSR&D Suicide Prevention Impact Network (SPRINT)
  Core Investigator and Associate Professor
  VA HSR&D Center to Improve Veteran Involvement in Care and Oregon Health & Science University
- Theresa Gleason, PhD
  Director
  Clinical Science Research & Development Service (CSR&D)

## Technical Expert Panel (TEP)

To ensure robust, scientifically relevant work, the TEP guides topic refinement; provides input on key questions and eligibility criteria, advising on substantive issues or possibly overlooked areas of research; assures VA relevance; and provides feedback on work in progress. TEP members are listed below:

- Elizabeth Karras-Pilato, PhD
  Co-Research Director and Clinical Senior Instructor
  VA VISN 2 Center of Excellence for Suicide Prevention and University of Rochester
- Alan Teo, MD
  Physician Investigator and Associate Professor
  VA HSR&D Center to Improve Veteran Involvement in Care and Oregon Health & Science University
- Lindsey Monteith, PhD
  Clinical Research Psychologist
  VA Rocky Mountain MIRECC
- Julie Cerel, PhD
  Clinical Psychologist and Professor
  University of Kentucky

## Peer Reviewers

The Coordinating Center sought input from external peer reviewers to review the draft report and provide feedback on the objectives, scope, methods used, perception of bias, and omitted evidence. Peer reviewers must disclose any relevant financial or non-financial conflicts of interest. Because of their unique clinical or content expertise, individuals with potential conflicts may be retained. The Coordinating Center and the ESP Center work to balance, manage, or mitigate any potential nonfinancial conflicts of interest identified.