# SUMMARY AND DISCUSSION

We conducted a systematic review and prepared a corresponding evidence map on the social-ecological risk and protective factors for suicide and suicide attempts among Veterans and active military.

We identified 55 studies rated as either low or moderate risk of bias published since 2011. Six were prospective studies with 4 (2 low risk of bias) examining risk factors for suicide deaths. Based on the available evidence we found that: 1) the quality and quantity of information was limited due in part to study design, multiplicity of reporting using similar data sources, variation in outcome reporting, potential lack of adequate adjustment for confounding factors, and possibly results-driven reporting; 2) the greatest amount of information was related to individual risk factors and came from retrospective cohort studies, many of which had moderate risk of bias; 3) information from prospective cohort and low risk of bias studies suggested that a history of prior suicide ideation or attempts, mental illness (not including PTSD), and substance, alcohol, or tobacco use are consistently predictive of, or associated with, suicide and attempts; 4) PTSD, unlike depression, anxiety, and other common mental disorders studied, was not consistently associated with suicide; 5) from the relational domain, marital status was not consistently associated with suicide or attempts, while relationship difficulties were generally found to be risk factors; 6) community level, relational level, and other individual level factors were reported in only 1 or 2 studies. These factors were sometimes associated with suicide and attempts, but the few studies limited confidence. Thus, further exploration of factors such as firearm status, marital status, and various forms of interpersonal violence is warranted; and 7) no studies reported on societal level factors.

Our report updates and expands on previous reviews evaluating suicide predictors in Veterans and active duty military.^37,38^ These reviews included literature published prior to 2011 and 2015 respectively, evaluated demographic and clinical factors, mainly included studies of individuals at known high risk, primarily described “risk prediction tools” used and their accuracy in these populations, and did not use the CDC Social-Ecological Model to evaluate studies and summarize results.

We urge caution in the interpretation and application of our findings. This report was intended as an evidence map of risk and protective factors using the Social-Ecological Model, which has utility for learning where research is concentrated and gaps that need to be addressed. We limited studies to those evaluating general populations of Veterans or active duty military not at otherwise known increased risk for suicide. Studies in other populations may also be informative, including general community populations and high-risk clinical samples. The factors assessed and categories used to assess risk domains often varied considerably in their definition. Findings were infrequently reported in more than 1 study, and when reported by multiple studies, factors were often defined differently. Consensus around which risk factors to include and their measurement has the potential to increase comparability of findings across studies and advance the field. The models used to assess the independence of reported factors also varied and there remains a high potential that unmeasured confounders are explanatory. Additionally, results could be dependent on thresholds or methods used to define the factor or the variables controlled. Reported results may either be due to chance or lack of power. There is a limited body of research examining multiple factors and their potential additive or non-additive influence of suicide and attempts. Positive associations from studies other than prospective designs may be merely associations rather than prognostic risk or protective factors. Furthermore, for most identified risk factors the defined risk estimates were relatively modest. Suicide is a rare event in the general population (even among Veterans and active duty military). Therefore, implementing these findings in individuals may unnecessarily label many at increased risk or result in program development to mitigate risk in identified individuals that could be resource-intensive, burdensome, and costly, and result in harms from overdiagnosis and labeling of individuals who would never attempt or die by suicide.

## LIMITATIONS

Due to the heterogeneity of identified studies and the large number and variation in reporting of risk and protective factors, we prepared a systematic review and evidence map rather than a quantitative synthesis of results or detailed analyses of individual studies. We did, however, provide information on directionality of effect and reported on study design, risk of bias, and analytic methods, thus enriching the information available typically shown in evidence maps.

Evidence maps identify gaps in knowledge and/or future research needs and present results, often in figures or graphs, or as a searchable database.^40^ Evidence maps may serve as a first step to a systematic review to identify gaps in a topic area. We identified many gaps in the quantity and quality of evidence that limits our ability to draw conclusions and provide immediate policy/practice considerations.

There were only 2 low risk of bias prospective studies specifically designed to address the key questions or risk factors. Inclusion of low risk of bias retrospective studies provides additional information but prognostic effects of evaluated factors cannot be inferred from retrospective data. Even when including lower methodologic quality studies, individual risk/protective factor results were informed by few studies. The details regarding variable inclusion in analytic models to control for potential confounding and determine the independent effect of reported factors on deaths and attempts varied and were difficult to adequately assess. There was little information regarding the conceptual frameworks used to select variables or thresholds used in the various models and whether the analyses were conceived of a priori. Many studies were derived from the same databases and thus are unlikely to be truly independent regarding their findings. We based our assessment of whether a factor was a risk or protective factor solely on the author-defined statistical significance of their findings. It is possible that some statistically significant results were due to chance or data-driven analyses or were very small in magnitude while some statistically nonsignificant results were due to poor statistical power and accompanying wide confidence intervals that could miss potentially clinically important findings.

Finally, available information generally infers associations rather than prognosis of factors with suicide or attempts. Consensus was reached in consultation with our partners and technical expert panel members on how to broadly categorize various factors and their domains. Authors used varying definitions of risk and protective factors. We attempted to discuss the specific factors used in each of the domains, especially when describing prospective cohort and low risk of bias studies, as results may vary due to variations in the factors or definition of given factor included in the specific domain. It is possible that different interpretations or categorizations may result in differing perspectives on our evidence map. In summary, our ability to reliably assess reported findings/validity/reproducibility was problematic.

### Study Quality

In general, the methodological quality of included studies was limited. Only 13 studies were assessed to be low risk of bias and only 6 were designed prospectively. Multiple reports used the same or similar databases for their analyses and thus findings are likely limited in their independent assessment or reproducibility. Furthermore, authors did not fully describe the models used to assess the independent risk or protective effect. There are no well-established analytic models or confounding factors of interest to control for in analytic models. Additionally, it is not clear why certain thresholds or variables were used or whether results were data rather than hypotheses driven. It is not known whether authors adequately adjusted for confounders, if analyses were post-hoc/data driven, or whether negative results were not consistently reported.

### Heterogeneity

We created an evidence map to summarize findings across study design, methodological quality and outcomes reported. We also summarize the populations assessed including Veteran versus active duty military and time in service. Rather than pooling results we describe results across study design and risk of bias. We described results separately for prospective cohort studies and for any study rated as low risk of bias. Therefore, readers can focus on the results presentation of this report that are most useful for them: eg, according to study population (Veteran or active duty); risk factor domain (individual, relational, community); study design (prospective, retrospective…); risk of bias (low vs low plus moderate). However, the results are already limited and additional attempts to determine whether findings were consistent or varied across other subgroups was not methodologically useful.

### Applicability of Findings to the VA Population

Our findings are highly applicable to the VA population. We targeted inclusion to studies of US Veterans or active duty military. We excluded studies only reporting individuals known to be at increased suicidal risk, typically due to mental health concerns or prior suicide attempts.

## RESEARCH GAPS/FUTURE RESEARCH

The currently available evidence is perhaps most notable for its limitations, gaps, and difficulty and thus emphasizes the need for future research in the areas of social-ecological factors for suicide. Because suicide is fortunately a rare event, assessing prognostic factors in those not known to be at markedly elevated risk requires very large sample sizes and long follow-up. Additionally, interventions known to reduce suicide risk or alter known risk factors may differentially affect suicide and attempts, thus making study of unknown factors difficult. However, given the large individual and societal impact of suicides and attempts research to determine risk and protective factors and develop strategies to mitigate these events is valuable. Additional creation of large cohorts to prospectively collect data specifically targeted to potential social-ecologic factors in general populations or those not to be at known marked increased risk based on sociodemographic, race/ethnicity, age, or sex would be useful. Utilization of large administrative/clinical data sets is helpful for efficiently collecting data on clinical diagnoses, healthcare service use, and other centrally collected health information. However, additional, more granular information related to community, relational, societal, and individual levels will likely require innovative survey methods. The current social-ecological model is useful for conceptualizing broad domains. Our attempt at categorizing identified factors into these domains and then subdomains is 1 possible strategy for exploring factors. Additional research is needed to better identify factor classification and definitions used to categorize and standardize factor reporting. More refined analytic methods to adjust for known and potential confounders is important and would lead to a better understanding of whether results are due to exploratory analyses, chance, or limited statistical power. Additional work is needed to validate and harmonize how factors and confounders are operationalized, measured, and reported, as well as the analytic models used.

## CONCLUSIONS

This systematic review and accompanying evidence map highlights main areas of information as well as gaps in the evidence according to study design and potential prognostic factors across the Social-Ecological Model among general populations of Veterans and active duty military. What information does exist is mainly from moderate risk of bias retrospective studies and describes risk factors within the social-ecological individual domain. Individual level social-ecological domain factors, especially mental illnesses and alcohol, drug, or tobacco use, as well as prior suicide attempts or ideation, may be the best currently supported risk factors for suicide and attempts. Information on military traumas and sexual or family violence generally showed positive associations with suicide. There were no data on societal level factors. There was little information regarding factors protective against suicide. Risk factor definitions and analyses varied considerably across reports and many were derived from multiple publications involving similar population databases. Standardization of risk factor definitions and comprehensive adjustments for potential confounding variables would aid our understanding of the association between these factors and suicidality, both individually and in concert with other factors.