# RESULTS

## OVERVIEW OF ALL ELIGIBLE STUDIES

After removing duplicates, we identified 1,351 citations for title and abstract triage. We reviewed the full text of 295 articles and identified 63 which met our inclusion criteria (Figure 2).

The majority (k=36) of studies were from large database s with sample sizes ≥ 100,000. Few studies (k=8) had sample sizes < 1,000. Most studies did not report the era of service for their samples, but when reported, the most common era of service was Operation Enduring Freedom/Operation Iraqi Freedom (OEF/OIF) for both active duty and Veterans. Most studies were retrospective cohorts by design (k=41) and few studies (k=7) were prospective cohort studies (Table 3).

Seventeen studies used data from the Study to Assess Risk and Resilience in Service members (STARRS) (Table 3). Most studies (k=52) combined 1 or more large databases, typically Veteran’s Health Administration (VHA) or Department of Defense (DoD) with other databases such as the National Death Index (NDI). The remaining 11 studies used only 1 data source, either VHA or DoD data. It is likely that many studies evaluated overlapping groups of individuals and predictive variables though it was not possible to determine.

No eligible studies reported on risk or prognostic factors in the societal domain of the Social-Ecological Model; few studies (k=3) reported on factors within the community domain. Almost all studies (k=57) reported on factors within the individual domain, and approximately one-third (k=24) reported on relational factors. Of the 24 studies which reported a relational factor, the most common factor was marital status or problem with an intimate relationship (k=17).

Of the 63 eligible articles, 14 were rated as low ROB,^7,11,27,28,30,36,41–48^ 41 rated as moderate ROB,^6,8–10,12–26,31–33,35,49–66^ and the remaining 8 were rated as high ROB^67–74^ and not analyzed further. For all low and moderate ROB studies, detailed evidence tables containing study characteristics, risk or protective factors reported, variables used for adjustment in models to control for potential confounding effects and assess potential independent roles for the reported factors, and direction of identified effects can be found in Appendix Table D1.

Figure 2 Literature Flow

Table 3 Study Characteristics of All Eligible Studies

Study Characteristics | Risk of Bias
Study Characteristics | Low (k=14) | Moderate (k=41) | High (k=8) | Total (k=63)
Sample Size
<1,000 | 0 | 3 | 5 | 8
1,000-9,999 | 1 | 5 | 1 | 7
10,000-99,999 | 1 | 11 | 0 | 12
≥100,000 | 12 | 22 | 2 | 36
Population
Veteran | 11 | 22 | 2 | 35
Active Military | 5 | 20 | 6 | 31
Era of Service: Vietnam | 1 | 1 | 0 | 2
Era of Service: OEF/OIF | 6 | 8 | 2 | 16
Era of Service: Gulf War | 0 | 2 | 0 | 2
Social-Ecologic Domains
Individual | 14 | 36 | 7 | 57
Relational | 4 | 18 | 2 | 24
Community | 0 | 3 | 0 | 4
Societal | 0 | 0 | 0 | 0
Data Source
VHA (administrative data) | 10 | 18 | 0 | 28
DoD (administrative data) | 7 | 21 | 4 | 32
VA/DoD SDR | 1 | 4 | 0 | 5
STARRS | 1 | 14 | 2 | 17
Survey/Self-Report | 1 | 3 | 4 | 8
National Death Index | 9 | 15 | 1 | 25
Claims Data (CMS/Tricare) | 2 | 0 | 0 | 2
Other Military Data | 4 | 6 | 0 | 10
National Violent Death Reporting System | 0 | 1 | 1 | 2
Other Data Sources | 0 | 2 | 0 | 2
Study Design
Case-Control | 0 | 7 | 3 | 10
Cross-Sectional | 1 | 2 | 2 | 5
Prospective Cohort | 2 | 4 | 1 | 7
Retrospective Cohort | 11 | 28 | 2 | 41

CMS=Centers for Medicare/Medicaid Services; DoD=Department of Defense; OEF/OIF=Operation Enduring Freedom/Operation Iraqi Freedom; SDR=Suicide Data Repository; STARRS=Study to Assess Risk and Resilience in Servicemembers; VHA=Veterans Health Administration

## OVERVIEW OF STUDIES RATED LOW OR MODERATE RISK OF BIAS

### Key Messages

- The quality and quantity of information in Veterans and active duty military is limited, in part due to study design, multiplicity of reporting using similar data sources, variation in outcome reporting, inadequate adjustment for confounding factors, and possibly post-hoc analyses.
- The greatest amount of information is related to individual risk factors and comes from retrospective cohort studies, many of which have moderate risk of bias. No studies reported on societal level factors.
- Information from prospective cohort and low risk of bias studies among Veterans and active duty military suggests that individual level factors, such as a history of prior suicide ideation or attempts, mental illness (other than posttraumatic stress disorder), and substance, alcohol, or tobacco use are consistently predictive of, or associated with, suicide and attempts.
- Posttraumatic stress disorder, another individual level factor, was not consistently associated with suicide.
- Community level, relational level, and other individual level factors were reported in only 1 or 2 studies. These factors were sometimes associated with suicide and attempts, but the few studies limited confidence. Thus, further exploration of factors such as firearm status, marital status, and various forms of interpersonal violence is warranted.

### Summary of Findings

Of the 55 studies rated low or moderate ROB, 50 reported on individual level factors, 22 reported on relational level factors, 3 reported on community level factors, and zero reported on societal level factors. Table 4 summarizes the number of studies which reported on risk or protective factors organized by the SEM. For many factors, results were informed by few studies with moderate ROB as details about factors used to control for potential confounding and determining the independent effect of the identified factors on deaths and attempts in the models, were difficult to adequately assess. Furthermore, there was little information regarding the selection of variables or thresholds used in the various models and whether the analyses were conceived a priori. Thus, assessing reported findings validity/reproducibility was problematic. Additional information on individual studies is included in Appendix B (ROB assessments) and Appendix D (evidence tables).

The most commonly reported factors at the individual level, in addition to demographic factors (age, race, sex, etc) and education were posttraumatic stress disorder (PTSD), other mental illnesses (ie, depression or anxiety), and alcohol, drug, or tobacco use (Table 4). Healthcare service use, criminal or legal problems, as well as military and deployment status, were also frequently noted. Firearm ownership and storage was only reported in 1 study despite firearms identified as a leading cause of suicide in Veterans. Ten studies explored the association of previous suicide attempt or ideation with future attempts or suicide.

At the relational level, marital status and relationship problems were most frequently reported.

Figure 3 further refines the identified risk/protective factors in a heat map stratified by study design. Individual risk factors were most frequently reported and consistently described across study design. The heat map also illustrates the limited amount of evidence from many of the reported factors even when looking across study design. Furthermore, as we describe the sections for the risk factor domains, many of the risk factors that we grouped in a single broad category (eg, alcohol, drug, or tobacco use) often used varying definitions or specific components of the category to assess the factor. Thus, the heat map provides an upper limit of the frequency and consistency of reporting across broad categories.

Table 5 provides the direction of the effect for each study which reported a risk or protective factor based on statistical significance as reported by study authors. Risk factors (ie, increased risk for suicide or attempt) are indicated as an upward arrow; protective factors (ie, decreased risk) are indicated as a downward arrow; and no association is indicated as horizontal double pointed arrowed. Individual results from each low risk of bias study are shown with blue arrows, moderate risk of bias in orange. Forty studies reported on suicides (4 prospective and 28 retrospective cohort studies) and 19 reported on attempts (3 prospective cohort, 13 retrospective cohort, and 3 case-control studies). While most studies reporting on a factor identified that factor as a risk rather than a protective factor, the findings were often from only 1 or 2 studies (and frequently using varying definitions of the factor. The figure illustrates the large identified gaps in evidence and the finding that most results were from moderate (rather than low) ROB studies. Results from each study that found “no effect” are shown with horizontal arrows without a discussion of the direction of the point estimate or the uncertainty that might be seen in the reported confidence intervals.

Table 4 Risk/Protective Factors Identified in Studies Rated Low/Moderate Risk of Bias (k=54)

Risk Factors | Number of Studies (k)
Individual Level
Previous suicide attempt/suicidal ideation | 10
Posttraumatic stress disorder | 12
Other mental illness (eg, depression, anxiety, psychiatric conditions) | 22
Emotions, such as anger, numbness, or hopelessness | 4
Alcohol, tobacco, and/or drug use | 17
Physical illness or pain | 8
Sleep disorders | 4
Cognitive or physical decline in functioning | 3
Body mass index | 2
Healthcare services use | 10
Criminal or legal problems | 7
Financial problems | 2
Job problems or loss | 5
Homelessness or housing instability | 4
Life stressors (non-specific) | 8
Firearm ownership/use/storage/accessibility | 1
Demographics (eg, age, sex, race, education) | 22
Sexual minority status | 1
Transition from incarceration to civilian life | 1
Military occupation | 7
Military rank | 9
Service connected (service-related disability) | 2
Deployment status | 14
Service branch | 5
Service component | 5
Time spent in service | 9
Time deployed | 3
Time since military separation | 4
Military part-time vs full-time | 1
Military former vs current service member | 2
Relational Level
Adverse childhood experiences | 1
Bullying | 1
Relationship problems (eg, break-up, violence, or loss) | 9
Sexual violence | 4
Marital status | 12
Social isolation/perceived burdensomeness/thwarted belongingness | 3
Death of a loved one or pet | 1
Community Level
Access to mental health care | 0
Monthly IED rates | 1
Military unit suicides | 1
Military-related chemical exposures | 1

Figure 3 Risk and Protective Factors for Suicide Deaths and Attempts, Stratified by Study Design

Table 5 Direction of Effect on Suicide Deaths and Attempts

Risk/Protective Factor | | Prospective Cohort (k=6) | | Retrospective Cohort (k=39) | | Case-Control (k=7) | | Cross-Sectional (k=3)
Risk/Protective Factor | | Deaths (k=4) | Attempts (k=3) | Deaths (k=28) | Attempts (k=13) | Deaths (k=6) | Attempts (k=3) | Deaths (k=3) | Attempts (k=0)
Individual (k=50) | Previous suicide attempt/ideation | | | ↑↑↑ ↑ | ↑ ↑↑ | ↑; ↔↔ | ↑↑ | ↑
Individual (k=50) | PTSD | ↔ ↔ | | ↑↑ ↑; ↓↓ ↓ | ↑ ↑↑ | | ↑ | ↑
Individual (k=50) | Other mental illnesses (eg, depression and anxiety) | ↑ ↑ | ↔ | ↑↑↑↑ ↑↑; ↓ | ↑ ↑↑↑↑↑; ↔ | ↑↑↑↑ | ↑↑; ↔ | ↑
Individual (k=50) | Emotions, such as anger, numbness, or hopelessness | | ↔ | ↑ | ↔ | ↔
Individual (k=50) | Alcohol and/or drug use | ↑↑ ↑ | | ↑↑↑↑ ↑↑; ↔ | ↑ ↑; ↔ | ↑↑; ↔ | ↑↑↑ | ↑
Individual (k=50) | Physical illness or pain | ↑ | ↔ | ↑↑; ↓; ↔ | ↔ | | | ↑
Individual (k=50) | Sleep disorders | | | | ↔ | ↔ | ↑ | ↑
Individual (k=50) | Cognitive or physical decline in functioning | ↑; ↔ | ↑ | | | ↑
Individual (k=50) | BMI (overweight or obese) | | | ↓ | | | ↓
Individual (k=50) | Health care services use | | | ↑↑↑; ↓; ↔ | ↑; ↔ | ↑ | | ↑; ↓
Individual (k=50) | Criminal or legal problems | | ↑ | ↑; ↔ | ↑; ↔ | ↑; ↔↔ | ↔↔
Individual (k=50) | Financial problems | | | | | ↔↔ | ↔
Individual (k=50) | Job problems or loss | | | ↑ | ↑ | ↔↔ | ↔ | ↑
Individual (k=50) | Homelessness | | | ↑↑; ↔ | ↑ | | | ↑
Individual (k=50) | Life stressors (non-specific) | ↔ | ↔ | ↑↑ | ↑; ↔ | ↔ | | ↑
Individual (k=50) | Firearm ownership, use, storage, accessibility | | | | | ↑
Individual (k=50) | Sexual minority status | | | ↑
Individual (k=50) | Transition from prison to civilian life | | | ↔ | ↑
Individual (k=50) | Military rank (enlisted/lower rank) | ↔ | ↔ | ↑↑; ↔ | ↑↑ | ↑ | | ↑
Individual (k=50) | Service connected (received VA disability benefits) | | | | | ↓ | | ↑
Individual (k=50) | Service branch (Army/Marine) | ↔ | | ↑↑; ↔ ↔
Individual (k=50) | Service component (active vs reserves) | ↔ | | ↑ ↑; ↔ | ↑
Individual (k=50) | Less time in service | | | ↑↑ ↑ | ↑↑↑↑↑ | ↑
Individual (k=50) | Longer time or larger proportion of time deployed | ↑; ↓ | | | ↑
Individual (k=50) | Shorter time since military separation | | | ↑ ↑↑; ↔
Individual (k=50) | Part-time National Guard | | | | | ↑
Individual (k=50) | Military former service member vs current | ↔ | | ↑
Relational (k=22) | Adverse childhood experiences | ↑
Relational (k=22) | Bullied within military unit | | ↑
Relational (k=22) | Relationship problems (eg, break-up, violence, or loss) | ↑ | ↔ | ↑ | ↑↑ | ↑↑↑; ↔ | ↑↑
Relational (k=22) | Sexual violence | | | ↑ | ↑; ↔ | | | ↑
Relational (k=22) | Marital status (unmarried) | ↔ ↔ | | ↑ ↑↑ | ↑ ↑; ↔↔↔ | ↔↔ | | ↔
Relational (k=22) | Social isolation/ perceived burdensomeness/ thwarted belongingness | ↑ | ↔ | | | ↔
Relational (k=22) | Death of a loved one or pet | | | | | ↔
Community (k=3) | Monthly IED rates | | | | ↑
Community (k=3) | Military unit suicides | | | | ↑
Community (k=3) | Military-related chemical exposure | | | ↔

BMI = Body mass index; IED= Improvised explosive devices; PTSD = Post traumatic stress disorder; VHA = Veterans Health Administration; VA = Department of Veterans Affairs

↑=increased risk

↓=decreased risk

↔=no difference or inconsistent

Blue=Low risk of bias study

Orange=Moderate risk of bias study

Notes: Each arrow represents results from a single study. Direction of effect based on reported p-values and confidence intervals. Across articles, there is overlap (to an unknown degree) in populations when the same administrative databases were used. Definitions of risk/protective factors across articles varied for several factors shown in table.

Demographics, military occupation, and deployment to combat zone are not shown in this table.

### Individual Level

The Individual domain of the Social-Ecological Model consists of factors pertaining to personal characteristics, such as demographics, health, or attitudes.^5^ We identified 50 studies that reported on individual risk factors. Of the 50 studies identified, 25 had a study population size ≥ 100,000, 30 captured the Veteran population, 25 made use of a VHA data source, and 29 made use of a DoD data source. Among the 50 studies that assessed individual risk or protective factors, 19 also assessed relational risk or protective factors and 3 evaluated community level risk or protective factors. These risk/protective factors were categorized into 26 subdomains which aligned with mental health conditions or health resource use, marital status, financial, legal or life/job stressors, or military service.

Among the identified 50 studies, 6 were of a prospective study design.^6–11^ Of the 6 prospective cohort studies, 4 reported on suicides and 3 reported on attempts. Two of the 6 were rated low risk of bias, evaluated ≥ 100,000 individuals, and reported on suicides; neither reported attempts. One study focused on Veterans and used VHA medical records^7^ while the other involved active duty military from Operation Enduring Freedom/Operation Iraqi Freedom (OEF/OIF) and used a variety of DoD data sources.^11^

All 4 moderate risk of bias studies evaluated active duty military personnel.

PTSD, other mental illnesses, and alcohol and/or drug use, as well as prior suicide attempts or ideation, were commonly reported as risk factors for both suicides and suicide attempts. The evidence identifying these variables as risk factors was generally consistent, primarily captured from retrospective or case-control studies, and found in both low and moderate risk of bias studies. PTSD was consistently shown to be a risk factor for suicide attempts, but results were inconsistent for suicide deaths.

Very few studies were prospective in nature with minimal overlap regarding the study risk factor of interest. Only the risk factors “other mental illness” and alcohol, tobacco, or drug use were evaluated by more than 1 prospective study and found to be a predictor of suicide. With little overlap of risk/protective factors between studies, there was less evidence to evaluate risk/protective factors on suicide attempts.

The evidence regarding other risk/protective factors, such as pain, healthcare service use, criminal or legal history, or financial or life stressors was sparse and less consistent across studies. Among the risk or protective factors related to the military, deployment status was captured by the largest number of studies, 14 in total. Military service variables such as less time in service and separation from service were also associated with both deaths and attempts. Increased body mass index (BMI) was determined to be a protective factor in 2 moderate risk of bias studies. Marital status (unmarried) was generally found to be a risk factor for suicide.

Housing instability (unstably housed and imminent risk for housing instability) was reported to increase risk of suicide death in 1 low ROB study.^30^ Homelessness was found to increase risk of suicide deaths in 2 studies (both by the same author and rated moderate ROB),^63,64^ while another low ROB study found no effect for suicide deaths, but an increase in suicide attempts.^27^

Two risk factors, military occupation and deployment status, were variably defined across the included studies. Seven studies describe an association between military occupation and suicide risk and 14 studies (low and moderate risk of bias) describe the association between deployment status and suicide risk (Appendix Table D2 and Appendix Table D3). Five of the studies investigating military occupation or job class used a version of combat occupation versus no-combat occupation; 2 of the 5 found no association and the remaining 3 found an increased risk of suicide^48^ and increased risk of suicide attempt^23,33^ for those with an occupational classification that included combat. The other 2 studies used very specific occupational titles; the first^47^ found no association between job class and risk of death from suicide and the second^11^ found a protective effect among those with a higher pay grade (E04-E07 vs E01-E03) and risk of death from suicide. Deployment status among the included studies referred to whether the individual had ever been deployed, was currently deployed, the number of deployments, whether the deployments had been to a combat region (OEF/OIF or Kosovo/Bosnia), or some combination of the previous categories. Three studies^23,24,32^ investigated currently versus previously versus never deployed and suicide attempt risk. Never and previously deployed were found to be risk factors for suicide attempts but not currently deployed.

### Relational Level

The Relational domain of the Social-Ecological Model contains direct person-to-person interaction, such as interpersonal relationships, social support, and family.^5^ We identified 22 studies that reported on such factors; 18 were rated moderate ROB^6,8,9,12–26^ and 4 were rated low ROB.^11,27,28,30^ Studies reported a variety of factors at the relational level, including marital status, relationship problems, sexual violence, history of family violence, adverse childhood experiences, bullying within military unit, social isolation, perceived burdensomeness, thwarted belongingness, and death of a loved one or pet.

Several studies (k=12) reported on marital status, with most reporting no significant effect for suicidal behaviors (k=8^9,11,13,15,17,18,23,24^) and few (k=4^19,25,27,29^) reporting unmarried (single, widowed, divorced, separated, or never married) individuals were at increased risk for both suicides and attempts. Seven studies reported on relationship problems, including recently failed intimate relationships, and recent divorce or counseling. Five of these studies (including 2 low ROB) reported these factors increased risk for suicides and attempts,^11,16,17,22,28^ while 2 reported no significant differences.^6,13^

Military sexual trauma was reported to increase risk for suicide death in 1 low ROB study.^30^ Three moderate ROB studies also reported on sexual violence: 1 reporting military sexual trauma increased risk of suicides for both men and women,^20^ the second reporting sexual assault victim status increased risk for suicide attempts,^21^ and the third study found no significant effect of a history of sexual or physical abuse on suicide attempts.^14^

Two moderate ROB studies reported no significant increase in suicide risk for those reporting perceived burdensomeness,^8^ thwarted belongingness,^8^ or social isolation.^13^ One low ROB study reported decreased social support increased risk of suicide.^11^

Two moderate ROB studies reported a history of family violence increased risk for suicide attempts.^23,26^ One low ROB study reported an Adverse Childhood Experiences score of ≥ 4 increased risk for suicide as an adult.^11^ One moderate ROB study reported that being bullied within your military unit increased risk of suicide attempts.^6^ One moderate ROB study reported no significant increase in risk of suicide behavior for those suffering from grief or loss of a loved one or pet.^13^

### Community Level

The Community domain of the Social-Ecological Model contains factors which are bounded to a certain region or area, like neighborhoods, schools, or workplaces.^5^ We identified 3 studies which reported on factors in this domain; all rated moderate ROB.^31–33^ All 3 studies reported on military-related factors: monthly improvised explosive device rates, unit suicides, and exposure to nerve gas.

Two studies used data from STARRS, the first reported that an increase in the frequency of monthly improvised explosive device incidents (as measured by the Joint IED Defeat Organization) increased risk for suicide attempts (moderate ROB),^32^ and the second reported as the number of suicide attempts in a military unit increased, so did individual risk for suicide attempt (moderate ROB).^33^

One moderate ROB study^31^ found no significant effects of nerve gas exposure on risk of suicide deaths.

### Societal Level

The Societal domain of the Social-Ecological Model contains large-scale issues such as social and cultural norms, policies, or other guiding rules and laws.^5^ Our review did not identify any studies which met our inclusion criteria that reported on these factors.

### Summary of Findings from Prospective Cohort Studies

We summarize findings from the 6 prospective cohort studies^6–11^ because their prospective design generally provides more reliable information on whether assessed factors are predictive of suicide rather than merely associated with suicide (Table 6). Overall, 4 studies reported on suicide and 3 reported on suicide attempts. One of these studies reported on both suicides and attempts.^10^ Two were considered low ROB and both reported on suicides (1 in Veterans^7^ and 1 in active military^11^). Of the 4 reports evaluating suicide, only 2 assessed more than a single predictive factor.^9,11^ The other 2, Bohnert^7^ and Naifeh,^10^ assessed the role of tobacco use in Veterans and cognitive decline in active military members, respectively. Three reports used data from the STARRS database and all were considered moderate ROB.^6,8,10^ The only prospective cohort study that utilized STARRS data to assess suicides was by Naifeh et al.^10^ No prospective cohort studies reported on either community or societal level factors.

Both low ROB studies with a prospective study design assessed the role of tobacco use on suicides and found an increased risk when controlling for other factors.^7,11^ Bohnert^7^ made use of VHA electronic medical record information and only assessed the predictive effect of tobacco use on suicide. They found that a diagnosis of tobacco use disorder was associated with suicides among Veterans when controlling for age group, sex, Charlson comorbidity score, VHA service connection, substance use disorder, bipolar disorder, depression, other anxiety disorder, posttraumatic stress disorder, and schizophrenia. Philipps^11^ and colleagues evaluated tobacco and other drug use in OEF/OIF Active Military individuals as part of the Recruit Assessment Program study. However, only alcohol use was reported in models that adjusted for other confounding factors (depression, PTSD, adjustment disorder, and deployment). One moderate ROB study using data from the Millennium Cohort Study^34^ reported alcohol use, defined as heavy/binge drinking or alcohol-related problems identified on a screening question, was positively associated with suicides.^9^

The low ROB prospective study conducted in active duty military^11^ noted a number of risk factors predictive of suicide including: mental illness, history of traumatic brain injury (TBI), lack of high school education, the percentage of time deployed while in the military, and military occupation. OEF/OIF deployment was a protective factor against suicide, while a history of PTSD was not significantly associated with suicide (similarly reported in 1 other moderate ROB prospective cohort study^9^). In contrast, the number of deployments was positively associated with suicide attempts in a single moderate risk of bias study among active duty military.^6^

Table 6 Findings from Prospective Cohort Studies^a,^ ^b^

Risk/ Protective Factor | | Author, Publication Year, Population, Sample Size, Cohort Name
Risk/ Protective Factor | | Bernecker 2019^6^; Active Military; N: 10,000-99,999; STARRS | | Bohnert 2014^7^; Veteran; N: ≥ 100,000; VHA | | Chu 2020^8^; Active Military; N: 1,000-9,999; STARRS | | LeardMann 2013^9^; Veteran and Active Military; N: ≥ 100,000; Millennium Cohort Study | | Naifeh 2017^10^; Active Military; N: 10,000-99,999; STARRS | | Phillips 2017^11^; Active Military; N: ≥ 100,000; Recruit Assess Program
Risk/ Protective Factor | | SD | SA | SD | SA | SD | SA | SD | SA | SD | SA | SD | SA
Individual | PTSD | | | | | | | ↔ | | | | ↔
Individual | Other mental illnesses (eg, anxiety, depression) | | ↔ | | | | | ↑ | | | | ↑
Individual | Hopelessness | | | | | | ↔
Individual | Alcohol, tobacco, or other drug use | | | ↑ | | | | ↑ | | | | ↑
Individual | Physical illness or pain | | ↔ | | | | | | | | | ↑
Individual | Cognitive or physical decline in functioning | | | | | | | ↔ | | ↑ | ↑
Individual | Criminal or legal problems | | ↑
Individual | Life stressors (non-specific) | | ↔ | | | | | ↔
Individual | Military rank (enlisted vs officer) | | ↔ | | | | | ↔
Individual | Service branch (Army/Marine) | | | | | | | ↔
Individual | Service component (active vs reserves) | | | | | | | ↔
Individual | Longer time or larger proportion of time deployed | | | | | | | ↓ | | | | ↑
Individual | Military former vs current service member | | | | | | | ↔
Relational | Adverse childhood experiences | | | | | | | | | | | ↑
Relational | Bullied within military unit | | ↑
Relational | Relationship problems | | ↔ | | | | | | | | | ↑
Relational | Marital status^c^ | | | | | | | ↔ | | | | ↔
Relational | Social isolation/ perceived burdensomeness/ thwarted belongingness | | | | | | ↔ | | | | | ↑

SA = suicide attempts; SD = suicide deaths; STARRS = Army Study to Assess Risk and Resilience in Servicemembers

↑=increased risk

↓=decreased risk

↔=no difference or inconsistent

Low risk of bias study

Moderate risk of bias study

a Demographics, including education are not shown in this table.

b Military occupation and deployment status can be found in appendix tables.

c The 2 studies measuring marital status used different definitions. LeardMann et al evaluated not married relative to married. Phillips et al analyzed marital status during in-service and re-captured at later date. Phillips et al. also assessed whether individuals had received relationship counseling.

### Summary of Findings from Low Risk of Bias Studies

We identified 12 retrospective studies in addition to the 2 prospective cohort studies that were rated low ROB (14 total) and thus provide additional information. As summarized in Table 3, 12 studies involved more than 100,000 individuals, 11 studies enrolled Veterans, and 5 included active duty military. Individual factors were reported in 14 studies, and relational factors were reported in 4 studies. No studies reported on community or societal factors. All studies reported on suicides and 2 reported on attempts.

While 14 studies reported on individual risk factors, each unique risk factor was typically assessed in only 1 or 2 studies. The following risk factors were assessed in 3 or more low ROB studies: previous suicide ideation or attempts, mental illness, PTSD, and alcohol, drug, or tobacco use. Suicide ideation or previous attempts were positively associated with suicide in 3 retrospective studies, 2 in Veterans and 1 in active military.^27,28,35^ A history of mental illness was consistently associated with suicide in 4 studies (3 in Veterans and 1 in active military.^27,28,35,36^ In 4 of 5 retrospective studies, substance use disorder was associated with increased suicides, and in the 2 prospective studies tobacco use was also associated with increased suicide risk in both Veterans and active military. The effect of PTSD on suicides was inconsistent. Two retrospective studies found a positive association while 1 found a protective effect, and the single prospective study^11^ found no significant relationship with PTSD and subsequent suicide among active military.

Of the 4 low ROB studies reporting on relational factors, 2 were retrospective cohort studies, 1 cross-sectional, and 1 prospective cohort. One study in Veterans noted that Veterans who were divorced, widowed, or never married had an increased suicide risk compared to married individuals.^27^ Similarly, the report by Shen and colleagues^28^ also showed that being divorced was associated with an increased risk of suicide. Cusack et al reported that a history of military sexual trauma increased risk for suicide deaths.^30^ As noted above, Phillips^11^ was a prospective cohort study in active duty military. They found that adverse childhood experiences, relationship problems, and social isolation were associated with increased suicide while marital status had no significant association.