# METHODS

## TOPIC DEVELOPMENT

The topic was nominated by VA Health Services Research and Development to further develop research priorities and identify areas for future funding on suicide prevention in VA. We worked with the Operational Partners and a Technical Expert Panel to refine the scope, key questions, and inclusion/exclusion criteria. We developed a protocol with input from our partners and registered in PROSPERO (CRD4202123641). The following Key Question was developed: What are the risk and protective factors for suicidal behaviors (attempts or death by suicide) across social-ecological levels of risk?

## SEARCH STRATEGY

We searched MEDLINE, Embase, PsycINFO, and Sociological Abstracts (Appendix A) from January 2011 to January 2021. We limited our search from 2011 to avoid duplication with a 2012 VA ESP review that used inclusion criteria similar to the present review.^37^ We used Medical Subject Headings (MeSH) and title/abstract terms indicative of suicide outcomes and risk or protective factors. We supplemented these results with additional hand searches of bibliographies from recent systematic reviews and with references from our technical expert panel.

## STUDY SELECTION

Eligible citations were screened independently by 2 reviewers using Distiller SR (Distiller SR, Evidence Partners, Ottawa, Canada) with prespecified criteria. Citations moved to full-text review if either reviewer considered the citation eligible. At full-text review, agreement of 2 reviewers was needed for study inclusion or exclusion; disputes were resolved by discussion with input from a third reviewer, if needed.

We included observational studies in the English-language that evaluated “modifiable” risk or protective factors for suicides or suicide attempts (ie, not sex, race, or age) in samples drawn from general populations of US Veterans and active military personnel. Studies must have reported suicide deaths or suicide attempts as outcomes; studies which included only composite outcomes (eg, suicide deaths plus attempts as 1 outcome) were excluded. Studies that did not capture the risk or protective factor(s) prior to the outcome of suicide or suicide attempts were excluded. We also excluded studies of special populations (eg, those known to be high risk due to mental health diagnoses or past suicide attempts) unless results were reported separately for individuals not considered at increased risk. However, we included studies of a general population of Veterans or active Service members that described their study sample’s mental health diagnoses or past suicide attempts as risk factors.

Table 2 Inclusion and Exclusion Criteria

| Inclusion Criteria | Exclusion Criteria
Population | Community-dwelling US Veteran or active military population (18 years of age or older) | Studies including >50% participants with increased risk of suicide due to prior suicide attempters or with specific mental or physical health conditions known to increase suicide risk: depression; psychoses, PTSD, recent cancer diagnosis, or terminal illness (unless results are stratified); Studies looking explicitly at genetic factors associated with suicide risk
Intervention | NA | NA
Comparator | NA | NA
Outcomes | Suicide attempts, suicide deaths | Composite outcome of suicide deaths plus attempts
Timing | Risk factors must precede the suicide/suicide attempt | Studies that do not capture the outcome of suicide/suicide attempt prior to the risk factor(s) of interest in the study
Setting | United States | Any
Study Design | Observational population-based studies published January 2011 – January 2021 that examine risk factors for suicide deaths and/or suicide attempts. Studies will capture risk factors/variables of interest, prior to (preceding) the outcomes of interest (suicide, suicide attempt). | Systematic reviews, narrative reviews, case reports, editorials, commentary, conference abstracts, interventions, and non-English language publications
Prognostic or Risk Factors | Any | Studies looking at physiological, laboratory, or imaging studies will be excluded (must have a clinical history or risen to the level of diagnosis; ie, we would include diabetes as a risk, but not A1C levels as measured by laboratory tests)

## QUALITY ASSESSMENT AND DATA ABSTRACTION

Risk of bias (ROB) was assessed using the Quality In Prognosis Studies (QUIPS) tool.^4^ The QUIPS tool uses 6 domains to critically appraise studies of prognostic factors (participation, attrition, prognostic factor measurement, outcome measurement, study confounding, and statistical analysis and reporting). Any study which was rated high in 2 or more domains was considered high ROB overall. Any study which was rated low ROB in all 6 domains was considered low ROB overall. Studies which did not meet either of those conditions were considered moderate ROB overall. Ratings for all eligible studies can be found in Appendix B.

We abstracted data from eligible studies on study and population characteristics, number of participants, data source, prognostic factors reported, and outcomes reported. We also reviewed and reported the analytic models and variables used to assess for possible independent effects. For studies rated low or moderate ROB, we abstracted the direction of the association between the risk or protective factor and the outcome, based on statistical significance. ROB assessments and data abstraction were conducted by 1 trained reviewer and verified or modified by a second reviewer.

## DATA SYNTHESIS

Due to the heterogeneity of identified studies, the large number of identified risk and protective factors, and variation in reporting of risk and protective factors, we prepared an evidence map rather than a quantitative synthesis of results or detailed analyses of individual studies. Evidence maps involve a systematic search of a broad field to identify gaps in knowledge and/or future research needs and present results in a user-friendly format, often a visual figure or graph, or a searchable database.^40^ Evidence maps are useful when there is an abundance and a diversity of research as a first step to a systematic review on all or a portion of the topic or to identify gaps in a topic area. They display where research is concentrated and gaps that need to be addressed. Using the CDC Social-Ecological Model,^3^ we categorized the reported risk and protective factors into 1 of 4 domains: Individual, Relational, Community, or Societal. We summarize studies by categories within this framework without commenting on the results or findings of individual studies.

We also summarize findings from studies with the strongest methodological study design, prospective cohort studies. In addition to reporting of prospective cohort studies, we summarize findings from any low risk of bias study regardless of study design (prospective, retrospective cohort, case-control, cross-sectional) as other methodologic criteria are used to assess the credibility of findings for a given outcome, including attrition, analytic methods, and the measurement of prognostic factors, outcomes, and confounders.

## RATING THE BODY OF EVIDENCE

A formal certainty of evidence rating was not conducted as part of this review.

## PEER REVIEW

A draft version of this report was reviewed by content experts and VA operational partners. Their comments and our responses are presented in Appendix C and the report was modified as needed.